# Appendix I Learning and Memory: Passive Avoidance

Figure I-1

Learning and Memory: Passive Avoidance

(A) Descriptive features and results of studies expressed as percent change from control response. Click to see interactive graphic sorted by study. (https://hawcproject.org/summary/data-pivot/assessment/126/study-learning-and-memory-passive-avoidance/)Note: For Wang et al. (2004), percent control response value for passive avoidance (step-down test, number of shocks, session 2, day 30) could not be calculated due to a zero response (count) for the control. (B) Risk of bias across studies. (https://hawcproject.org/summary/visual/55/) (C) Risk of bias assessments for individual (https://hawcproject.org/summary/visual/54/) studies (https://hawcproject.org/summary/visual/54/)(*study excluded from primary analysis due to concerns for risk of bias).