# Appendix G Learning and Memory: Other Maze Tests

Figure G-1

Learning and Memory: Other Maze Tests

(A) Descriptive features and results of studies expressed as percent change from control response. Click to see interactive graphic sorted by study. (https://hawcproject.org/summary/data-pivot/assessment/126/study-learning-and-memory-maze-test/) Note: For Bhatnagar et al. (2002), data presented only for control and high dose groups (0-, 3.68-, 7.37-, and 14.72-ppm dose groups treated). (B) Risk of bias across studies. (https://hawcproject.org/summary/visual/49/) (C) Risk of bias assessments for individual studies (https://hawcproject.org/summary/visual/48/)(*study excluded from primary analysis due to concerns for risk of bias).