# Appendix F Learning and Memory: Y-Maze

Figure F-1

Learning and Memory: Y-Maze

(A) Descriptive features and results of studies expressed as percent change from control response. Click to see interactive graphic sorted by study. (https://hawcproject.org/summary/data-pivot/assessment/126/study-learning-and-memory-y-maze/)(B) Risk of bias across studies. (https://hawcproject.org/summary/visual/40/) (C) Risk of bias assessments for individual studies (https://hawcproject.org/summary/visual/39/)(*study excluded from primary analysis due to concerns for risk of bias).