# Appendix E Learning and Memory: T-Maze

Figure E-1

Learning and Memory: T-Maze

(A) Descriptive features and results of studies expressed as percent change from control response. Click to see interactive graphic sorted by study. (https://hawcproject.org/summary/data-pivot/assessment/126/study-learning-and-memory-t-maze/) (B) Risk of bias across studies. (https://hawcproject.org/summary/visual/37/) (C) Risk of bias assessments for individual studies (https://hawcproject.org/summary/visual/36/)(*study excluded from primary analysis due to concerns for risk of bias).