# Appendix D Learning and Memory: Morris Water Maze (All Studies)

Figure D-1

Learning and Memory: Morris Water Maze (All Studies)

(A) Descriptive features and results of studies expressed as percent change from control response. Click to see interactive graphic sorted by study. (https://hawcproject.org/summary/data-pivot/assessment/126/study-learning-and-memory-morris-water-maze/) Note: Some data from Liu et al. (2009) are also presented in Liu et al. (2011) (escape time, acquisition, day 6). Findings are presented under Liu et al. (2009) in the figure. Apparently, identical data were reported in Dong et al. (2015a); Dong et al. (2015b) and Dong et al. (2015c). Only data from Dong et al. (2015a) is presented in figure. (B) Risk of bias across studies. (https://hawcproject.org/summary/visual/34/) (C) Risk of bias (https://hawcproject.org/summary/visual/33/) assessments for individual studies (https://hawcproject.org/summary/visual/33/)(*study excluded from primary analysis due to concerns for risk of bias).