# Appendix C Studies Excluded from the Analysis for Having “Probably High” or “Definitely High” Risk of Bias in Multiple Critical Domains

Table C-1 Studies Excluded from Analysis for Risk of Bias

Click to See Risk of Bias Rationale | Study | No Randomization^1^ | Concern or Lack of Information on Exposure Characterization | Concern for Lack of Blinding Outcome Assessment^1^ | Lack of Control for Litter Effects^1^ | Other Factors
1 (https://hawcproject.org/rob/study/52469/) | Bǎran-Poesina et al. (2013) | X | X | X | X | Were outcome data incomplete due to attrition or exclusion from analysis? Not reported. 16 animals per group were treated but sample size was not reported for any results. Stated that 2 pairs of each F1 group were mated to create the F2 generation, but no information provided on how many animals were tested.
2 (https://hawcproject.org/rob/study/52447/) | Basha and Sujitha (2012) | X | X | X
3 (https://hawcproject.org/rob/study/52455/) | Basha et al. (2011) | X | | X | X | Were outcome data incomplete due to attrition or exclusion from analysis? Not reported. Stated that 8 dams in the F0 generation treated, but no indication of how many F1, F2, or F3 animals were tested. A few results tables for non-behavior outcomes state n = 6.
4 (https://hawcproject.org/rob/study/52463/) | Bera et al. (2007) | X | X | X
5 (https://hawcproject.org/rob/study/52468/) | Bhatnagar et al. (2002) | | | | | Were experimental conditions identical across study groups? Controls drank deionized, defluorinated water and were untreated and maintained “isolated in a corner of animal room for two days…kept undisturbed, and the room was locked for 18 hrs. Just after opening the animal room, all mice were sacrificed.” Similar housing conditions were not reported for treatment groups, which were described as receiving “…(NaF) orally, dissolved in water…
6 (https://hawcproject.org/rob/study/52451/) | Elliott (1967) | X | X | X
7 (https://hawcproject.org/rob/study/52490/) | Gopal et al. (2006) | X | X | | | Were experimental conditions identical across study groups? Controls did not receive treatment, and experimental conditions stated only to be “standard laboratory condition.”
8 (https://hawcproject.org/rob/study/52440/) | Han et al. (2014) | | X | X | | Were there any other potential threats to internal validity? Absence of expected response in control animals in exploratory behavior test.
9 (https://hawcproject.org/rob/study/52757/) | Hong et al. (2005) | | X | X | X | Were outcome data incomplete due to attrition or exclusion from analysis? Not reported. 6 dams treated in each group and offspring tested at PND30, 60, and 90, but number of offspring assessed not reported.
10 (https://hawcproject.org/rob/study/97858/) | Jain et al. (2015) | | X | X | | Were outcome data incomplete due to attrition or exclusion from analysis? Not reported and cannot be inferred, as neither number of treated animals nor animals assessed for behavioral effects reported. Were there any other potential threats to internal validity? Statistical analyses were reasonable (one-way ANOVA followed by Bonferroni post-test), but consideration of homogeneity of variance not reported. Sex of animals used or if equal numbers of each sex were used not reported. If both sexes were used, results were reported for the sexes together.
11 (https://hawcproject.org/rob/study/52445/) | Jetti et al. (2016) | X | X | X
12 (https://hawcproject.org/rob/study/52481/) | Liu (1989) | | X | X | X | Were outcome data incomplete due to attrition or exclusion from analysis? Unclear. 150 offspring generated from 70 dams were divided into 3 groups (unclear how many dams became pregnant in each group). Also unclear how many offspring were tested; results for 22 offspring reported in Table 1 (controls = 8; low fluoride = 7; high fluoride = 7).
13 (https://hawcproject.org/rob/study/52449/) | Mullenix et al. (1995) | | X | | X | Were outcome data incomplete due to attrition or exclusion from analysis? Death occurred in about half the weanlings exposed to 175 ppm. Unclear how much attrition in other treatments. Not all numbers reported and in some cases they do not sum to numbers of controls or treated animals. Were all measured outcomes reported? Unclear. Results appear most complete for animals whose treatment started at weaning or adulthood. Data presentation for RS statistic and K functions difficult to follow. K scores appear presented for only certain behavior clusters.
14 (https://hawcproject.org/rob/study/52461/) | Niu et al. (2009) | X | | X | X
15 (https://hawcproject.org/rob/study/52452/) | Niu et al. (2014) | X | X | | X
16 (https://hawcproject.org/rob/study/52541/) | Rumiantsev et al. (1988) | X | | X | | Were experimental conditions identical across study groups? Very few details on experimental conditions provided and whether control group was based on inhalation or oral administration unclear, as chemicals administered by different routes of administration but presented in a table with a single control group. Were outcome data incomplete due to attrition or exclusion from analysis? Not reported and cannot be inferred, as neither number of treated animals nor animals assessed for behavioral effects reported. Were all measured outcomes reported? Very little description in methods of procedure, sample sizes not reported, unclear whether SD or SE is reported in the results table. Were there any other potential threats to internal validity? Statistical methods not reported.
17 (https://hawcproject.org/rob/study/52475/) | Wu et al. (2008) | X | X | X | X | Were outcome data incomplete due to attrition or exclusion from analysis? Number of dams treated not clearly reported for all groups. Authors report that 6 of 18 litters in high dose group lost all pups due to no or low milk production. Table 2 reports results for 9−11 litters in each group. Considered to pose potential risk of bias because number of litters varies across groups and number of treated dams not reported in all groups and loss of pups in the high dose group. Results appear to be obtained on 40 pups in each group, but unclear for all outcomes. Were all measured outcomes reported? Unclear. Description of methods too incomplete to evaluate “Behavioral teratology testing of the offspring rats was conducted according to procedures outlined in the literature.” Were there any other potential threats to internal validity? Statistical methods not reported.
18 (https://hawcproject.org/rob/study/57043/) | Zhang et al. (2009) | | X | X | X | Were outcome data incomplete due to attrition or exclusion from analysis? Unclear. One dam treated per group, resulting in 37 F1 offspring (numbers range from 9−10 per group). Sample size in results not presented but no loss of animals reported.
19 (https://hawcproject.org/rob/study/52482/) | Zhang et al. (2001) | | X | X | | Were outcome data incomplete due to attrition or exclusion from analysis? Unclear. Authors did not report in the methods section number of mice treated and inferring is difficult because the number of mice among treatment and control groups differed and number of mice reported under same treatment group differed between Table 1 and Table 2.

^1^ Information often is not reported and is assumed not conducted, resulting in an assessment of “probably high” risk of bias. Authors were queried for missing information and responses received were used to update risk of bias assessments.