# Appendix B Data Extraction Elements for Animal Studies

Table B-1 Data Extraction Elements for Animal Studies

Data Type | Element
Funding | Funding source(s)
Funding | Reporting of COI by authors and/or translators (*reporting bias)
Animal Model | Sex
Animal Model | Species
Animal Model | Strain
Treatment | Chemical name and CAS number
Treatment | Source of chemical
Treatment | Purity of chemical (*information bias)
Treatment | Dose levels or concentration (as presented and converted to mg/kg bw/d when possible)
Treatment | Other dose-related details, such as whether administered dose level was verified by measurement, information on internal dosimetry (*information bias)
Treatment | Vehicle used for exposed animals
Treatment | Route of administration (e.g., oral, inhalation, dermal, injection)
Treatment | Age or lifestage at start of dosing and at health outcome assessment
Treatment | Duration and frequency of dosing (e.g., hours, days, weeks when administration was ended, days per week)
Methods | Study design (e.g., single treatment, acute, subchronic (e.g., 90 days in a rodent), chronic, multigenerational, developmental, other)
Methods | Guideline compliance (i.e., use of EPA, OECD, NTP or another guideline for study design, conducted under GLP guideline conditions, non-GLP but consistent with guideline study, non-guideline peer-reviewed publication)
Methods | Number of animals per group (and dams per group in developmental studies) (*missing data bias)
Methods | Randomization procedure, allocation concealment, blinding during outcome assessment (*selection bias)
Methods | Method to control for litter effects in developmental studies (*information bias)
Methods | Use of negative controls and whether controls were untreated, vehicle-treated, or both
Methods | Endpoint health category (e.g., reproductive)
Methods | Endpoint (e.g., infertility)
Methods | Diagnostic or method to measure endpoint (*information bias)
Methods | Statistical methods (*information bias)
Results | Measures of effect at each dose or concentration level (e.g., mean, median, frequency, measures of precision or variance) or description of qualitative results. When possible, OHAT will convert measures of effect to a common metric with associated 95% confidence intervals (CI). Most often, measures of effect for continuous data will be expressed as percent control response, mean difference, or standardized mean difference. Categorical data will be expressed as relative risk (RR, also called risk ratio).
Results | No observed effect level (NOEL), lowest observed effect level (LOEL), benchmark dose (BMD) analysis, statistical significance of other dose levels, or other estimates of effect presented in paper. Note: The NOEL and LOEL are highly influenced by study design, give no quantitative information about the relationship between dose and response, and can be subject to author’s interpretation (e.g., a statistically significant effect might not be considered biologically important). Also, a NOEL does not necessarily mean zero response. Ideally, the response rate or effect size at specific dose levels is used as the primary measure to characterize the response.
Results | If not presented in the study, statistical power can be assessed during data extraction using an approach that assesses the ability to detect a 10% to 20% change from control group’s response for continuous data, or a relative risk or odds ratio of 1.5–2 for categorical data, using the outcome frequency in the control group to determine sample size. Recommended sample sizes to achieve 80% power for a given effect size, i.e., 10% or 20% change from control, will be compared to sample sizes used in the study to categorize statistical power. Studies will be considered adequately powered when sample size for 80% power is met.
Results | Observations on dose response (e.g., trend analysis, description of whether dose-response shape appears to be monotonic, nonmonotonic)
Results | Data on internal concentration, toxicokinetics, or toxicodynamics (when reported)
Other | Documentation of author queries, use of digital rulers to estimate data values from figures, exposure unit, statistical result conversions, etc.