# Appendix A Electronic Database Search Strategies

## A.1 Biosis

Table A-1 Search Strategy for BIOSIS

Search ID | Search Terms | Date: Number of Records
# 4 | #1 AND #2 AND #3 | 2/18/2015: 899 1/14/2016 update: 21
# 1 Animal Studies | TOPIC: ((“animal model” OR “animal models” OR “invertebrates” OR “chordata” OR “vertebrates” OR “amphibians” OR “birds” OR “fishes” OR “reptiles” OR “mammals” OR “primates” OR “artiodactyla” OR “carnivora” OR “cetacea” OR “chiroptera” OR “elephants” OR “hyraxes” OR “insectivora” OR “lagomorpha” OR “marsupialia” OR “monotremata” OR “perissodactyla” OR “rodentia” OR “scandentia” OR “sirenia” OR “xenarthra” OR “haplorhini” OR “strepsirhini” OR “platyrrhini” OR “tarsii” OR “catarrhini” OR “cercopithecidae” OR “hylobatidae” OR “hominidae” OR “gorilla” OR “pan paniscus” OR “pan troglodytes” OR “pongo pygmaeus” OR animals OR animal OR mice OR mus OR mouse OR murine OR woodmouse OR rats OR rat OR murinae OR muridae OR cottonrat OR cottonrats OR hamster OR hamsters OR cricetinae OR rodentia OR rodent OR rodents OR pigs OR pig OR swine OR swines OR piglets OR piglet OR boar OR boars OR “sus scrofa” OR ferrets OR ferret OR polecat OR polecats OR “mustela putorius” OR “guinea pigs” OR “guinea pig” OR cavia OR callithrix OR marmoset OR marmosets OR cebuella OR hapale OR octodon OR chinchilla OR chinchillas OR gerbillinae OR gerbil OR gerbils OR jird OR jirds OR merione OR meriones OR rabbits OR rabbit OR hares OR hare OR diptera OR flies OR fly OR dipteral OR drosophila OR drosophilidae OR cats OR cat OR carus OR felis OR nematoda OR nematode OR nematodes OR sipunculida OR dogs OR dog OR canine OR canines OR canis OR sheep OR sheeps OR mouflon OR mouflons OR ovis OR goats OR goat OR capra OR capras OR rupicapra OR rupicapras OR chamois OR haplorhini OR monkey OR monkeys OR anthropoidea OR anthropoids OR saguinus OR tamarin OR tamarins OR leontopithecus OR hominidae OR ape OR apes OR “pan paniscus” OR bonobo OR bonobos OR “pan troglodytes” OR gibbon OR gibbons OR siamang OR siamangs OR nomascus OR symphalangus OR chimpanzee OR chimpanzees OR prosimian OR prosimians OR “bush baby” OR bush babies OR galagos OR galago OR pongidae OR gorilla OR gorillas OR “pongo pygmaeus” OR orangutan OR orangutans OR lemur OR lemurs OR lemuridae OR horse OR horses OR equus OR cow OR calf OR bull OR chicken OR chickens OR gallus OR quail OR bird OR birds OR quails OR poultry OR poultries OR fowl OR fowls OR reptile OR reptilia OR reptiles OR snakes OR snake OR lizard OR lizards OR alligator OR alligators OR crocodile OR crocodiles OR turtle OR turtles OR amphibian OR amphibians OR amphibia OR frog OR frogs OR bombina OR salientia OR toad OR toads OR “epidalea calamita” OR salamander OR salamanders OR eel OR eels OR fish OR fishes OR pisces OR catfish OR catfishes OR siluriformes OR arius OR heteropneustes OR sheatfish OR perch OR perches OR percidae OR perca OR trout OR trouts OR char OR chars OR salvelinus OR minnow OR cyprinidae OR carps OR carp OR zebrafish OR zebrafishes OR goldfish OR goldfishes OR guppy OR | 2/18/2015: 218,068,453 1/14/2016 update: 150,971
# 2 Neurological Outcomes | guppies OR chub OR chubs OR tinca OR barbels OR barbus OR pimephales OR promelas OR “poecilia reticulata” OR mullet OR mullets OR eel OR eels OR seahorse OR seahorses OR mugil curema OR atlantic cod OR shark OR sharks OR catshark OR anguilla OR salmonid OR salmonids OR whitefish OR whitefishes OR salmon OR salmons OR sole OR solea OR lamprey OR lampreys OR pumpkinseed OR sunfish OR sunfishes OR tilapia OR tilapias OR turbot OR turbots OR flatfish OR flatfishes OR sciuridae OR squirrel OR squirrels OR chipmunk OR chipmunks OR suslik OR susliks OR vole OR voles OR lemming OR lemmings OR muskrat OR muskrats OR lemmus OR otter OR otters OR marten OR martens OR martes OR weasel OR badger OR badgers OR ermine OR mink OR minks OR sable OR sables OR gulo OR gulos OR wolverine OR wolverines OR mustela OR llama OR llamas OR alpaca OR alpacas OR camelid OR camelids OR guanaco OR guanacos OR chiroptera OR chiropteras OR bat OR bats OR fox OR foxes OR iguana OR iguanas OR xenopus laevis OR parakeet OR parakeets OR parrot OR parrots OR donkey OR donkeys OR mule OR mules OR zebra OR zebras OR shrew OR shrews OR bison OR bisons OR buffalo OR buffaloes OR deer OR deers OR bear OR bears OR panda OR pandas OR “wild hog” OR “wild boar” OR fitchew OR fitch OR beaver OR beavers OR jerboa OR jerboas OR capybara OR capybaras) NOT (humans OR hominidae)) TOPIC: (“nervous system” OR “central nervous” OR brain OR blood- brain OR brain-stem OR cerebral OR limbic OR amygdala OR hippocamp* OR hypothalamus OR parahippocamp* OR perforant OR mesencephalon OR prosencephalon OR rhombencephalon OR meninges OR dura-matter OR spinal-cord OR ganglia OR ganglion OR nerve OR nervous OR neural OR neural near/0 tube* OR afferent OR auditory OR olfactory OR oculomotor OR optic OR retinal OR efferent OR perforant OR neuroglia* OR astrocyte* OR microglia* OR schwann near/0 cell* OR “myelin sheath” OR neuron* OR axon* OR dendrit* OR interneuron* OR lewy near/0 bod* OR neurofibril* OR purkinje-cell* OR pyramidal-cell* OR serotonergic OR neuromuscular OR neuroendocrine OR neurosecret* OR pituitary OR pineal OR synapse* OR synaptic OR presynaptic OR postsynaptic OR plasticity OR hearing OR vision OR taste OR smell OR propriocept* OR neurologic* OR autonomic-nervous OR central near/0 nervous OR demyelinat* OR “multiple sclerosis” OR myasthenia-gravis OR epilep* OR encephalitis OR meningitis OR chronic-fatigue OR dyskinesia* OR dyston* OR parkinson* OR mobility OR motor near/0 control OR motor near/0 abilit* OR motor near/0 skill* OR cranial near/0 nerve OR huntington* OR tourette* OR ataxia OR hydranencephaly OR neurofibra* OR tauopath* OR fibromyalgia OR myopath* OR neurodegenerat* OR neuroimmunomodulat* OR neuromuscular OR neuropath* OR neurosecret* OR neurotox* OR neurobehav* OR dyslexi* OR cognitive OR cognition OR intellect* OR intelligence OR mental-deficienc* OR mental near/0 deficit* OR down-syndrome OR rett-syndrome OR memory near/0 deficit* OR memory near/0 impair* OR memory-loss* OR mental near/0 disorder* OR developmental near/0 delay* OR developmental near/0 disabilit* OR anxiety OR obsessive-compulsive OR phobia* OR phobic OR antisocial OR personality OR schizophrenia OR behavior OR paranoid OR paranoia OR dementia OR senile OR senility OR alzheimer OR learning OR aphasia OR autism OR autistic OR “attention-deficit”) | 2/18/2015: 5,947,883 1/14/2016 update: 168,166 2/18/2015: 21,679
# 3 Fluoride | TITLE=(fluorid* OR flurid* OR fluorin* OR florin* OR fluorosis) NOT TOPIC=((18F OR F-18 OR “fluorine-18” OR 19F OR F-19 OR “fluorine-19” OR (PET AND scan) OR f-labeled OR imaging OR radioligand*)) | 1/14/2016 update: 450

## A.2 EMBASE

Search Note: Animal studies were restricted to the traditional animal models. Any other animal studies would likely be picked up in the other databases.

Table A-2 Search Strategy for EMBASE

Search ID | Search Terms | Date: Number of Records
# 4 | #1 AND #2 AND #3 | 1/7/ 2015: 306 1/14/2016 update: 25
# 1 Animal Studies | ‘animal model'/exp OR rats OR rat OR mice OR mouse OR rodent* OR murin* | 1/7/2015: 3,389,269 1/14/2016 update: 137,941
# 2 Neurological Outcomes | 'nervous system'/exp OR 'nervous system' OR 'central-nervous' OR 'brain'/exp OR brain OR 'blood brain' OR 'brain stem'/exp OR 'brain stem' OR cerebral OR cortical OR limbic OR 'amygdala'/exp OR amygdala OR hippocamp* OR 'hypothalamus'/exp OR hypothalamus OR parahippocamp* OR 'mesencephalon'/exp OR mesencephalon OR 'prosencephalon'/exp OR prosencephalon OR 'rhombencephalon'/exp OR rhombencephalon OR 'meninges'/exp OR meninges OR 'dura matter' OR 'spinal cord'/exp OR 'spinal cord' OR 'ganglia'/exp OR ganglia OR 'ganglion'/exp OR ganglion OR 'nerve'/exp OR nerve OR neural OR 'neural tube'/exp OR 'neural tube' OR afferent OR auditory OR olfactory OR oculomotor OR optic OR 'retinal'/exp OR retinal OR efferent OR perforant OR neuroglia* OR astrocyte* OR microglia* OR schwann NEAR/0 cell* OR 'myelin sheath'/exp OR 'myelin sheath' OR neuron* OR axon* OR dendrit* OR interneuron* OR lewy NEXT/0 bod* OR neurofibril* OR purkinje NEXT/0 cell* OR pyramidal NEXT/0 cell* OR serotonergic OR neuromuscular OR neuroendocrine OR neurosecret* OR 'pituitary'/exp OR pituitary OR pineal OR synapse* OR synaptic OR presynaptic OR postsynaptic OR 'plasticity'/exp OR plasticity OR 'hearing'/exp OR hearing OR 'vision'/exp OR vision OR 'taste'/exp OR taste OR 'smell'/exp OR smell OR propriocept* OR nervous AND system AND ('diseases'/exp OR diseases) OR neurologic* OR 'autonomic nervous' OR 'central nervous' OR demyelinat* OR 'multiple sclerosis'/exp OR 'multiple sclerosis' OR 'myasthenia gravis'/exp OR 'myasthenia gravis' OR epilep* OR 'encephalitis'/exp OR encephalitis OR 'meningitis'/exp OR meningitis OR 'chronic fatigue' OR dyskinesia* OR dyston* OR parkinson* OR mobility OR 'motor control'/exp OR 'motor control' OR motor NEXT/0 abilit* OR motor NEXT/0 skill* OR 'cranial nerve'/exp OR 'cranial nerve' OR huntington* OR tourette* OR 'ataxia'/exp OR ataxia OR 'hydranencephaly'/exp OR hydranencephaly OR neurofibra* OR tauopath* OR 'fibromyalgia'/exp OR fibromyalgia OR myopath* OR neurodegenerat* OR neuroimmunomodulat* OR neuromuscular OR neuropath* OR neurosecret* OR neurotox* OR neurobehav* OR dyslexi* OR cognitive OR 'cognition'/exp OR cognition OR intellect* OR 'intelligence'/exp OR intelligence OR mental NEAR/0 deficienc* OR mental NEAR/0 deficit* OR 'down syndrome'/exp OR 'down syndrome' OR 'rett syndrome'/exp OR 'rett syndrome' OR memory NEAR/0 deficit* OR memory NEAR/0 impair* OR memory NEAR/0 loss* OR mental AND disorders OR developmental AND disabilities OR developmental NEAR/0 delay* OR developmental NEAR/0 disabilit* OR 'anxiety'/exp OR anxiety OR 'obsessive compulsive' OR phobia* OR phobic OR antisocial OR 'personality'/exp OR personality OR 'schizophrenia'/exp OR schizophrenia OR 'behavior'/exp OR behavior OR 'paranoid'/exp OR paranoid OR 'paranoia'/exp OR paranoia OR 'dementia'/exp OR dementia OR senile OR 'senility'/exp OR senility OR alzheimer OR 'learning'/exp OR learning OR 'aphasia'/exp OR aphasia OR 'autism'/exp OR autism OR autistic OR 'attention deficit'/exp OR 'attention deficit' | 1/7/2015: 4,078,217 1/14/2016 update: 237,733
# 3 Fluoride | 2/18/2015: fluoride:de OR fluorid* NOT ('f labeled' OR 'fluorine 18'/exp OR 'fluorine 18' OR 'imaging'/exp OR imaging OR radioligand*) 1/14/2016 update: fluoride:de OR fluorid* OR flurid* OR fluorinated OR 'fluorosis'/exp OR fluorosis NOT ('18f'/exp OR 18f OR 'f 18'/exp OR 'f 18' OR 19f OR 'f 19' OR 'fluorine-19'/exp OR 'fluorine-19' OR (pet AND scan) OR 'f labeled' OR 'fluorine 18'/exp OR 'fluorine 18' OR 'imaging' OR 'imaging'/exp OR imaging OR radioligand*) AND [2015-2016]/py | 1/7/2015: 59,675 1/14/2016 update: 1,635

## A.3 PsycINFO

Search Note: Given how studies fluoride studies were included in this database, the search was not restricted to neurological outcomes in animals.

Table A-3 Search Strategy for PsycINFO

Search ID | Search Terms | Date: Number of Records
# 1 | 1/7/2015: Title: fluorid* OR flurid* OR fluorin* OR florin* 1/14/2016 update: Title: fluorid* OR flurid* OR fluorin* OR florin* OR fluorosis OR Abstract: fluorid* OR flurid* OR fluorin* OR florin* OR fluorosis AND Year: 2015 To 2016 | 1/7/2015: 74 1/14/2016 update: 36

## A.4 PubMed

Table A-4 Search Strategy for PubMed

Search ID | Search Terms | Date: Number of Records
# 4 | #1 AND #2 AND #3 | 1/7/2015: 2417 1/14/2016 update: 53
# 1 Animal Studies [from Hooijmans et al. (2010)] | (“animal experimentation”[MeSH Terms] OR “models, animal”[MeSH Terms] OR “invertebrates”[MeSH Terms] OR “Animals”[Mesh:noexp] OR “animal population groups”[MeSH Terms] OR “chordata”[MeSH Terms:noexp] OR “chordata, nonvertebrate”[MeSH Terms] OR “vertebrates”[MeSH Terms:noexp] OR “amphibians”[MeSH Terms] OR “birds”[MeSH Terms] OR “fishes”[MeSH Terms] OR “reptiles”[MeSH Terms] OR “mammals”[MeSH Terms:noexp] OR “primates”[MeSH Terms:noexp] OR “artiodactyla”[MeSH Terms] OR “carnivora”[MeSH Terms] OR “cetacea”[MeSH Terms] OR “chiroptera”[MeSH Terms] OR “elephants”[MeSH Terms] OR “hyraxes”[MeSH Terms] OR “insectivora”[MeSH Terms] OR “lagomorpha”[MeSH Terms] OR “marsupialia”[MeSH Terms] OR “monotremata”[MeSH Terms] OR “perissodactyla”[MeSH Terms] OR “rodentia”[MeSH Terms] OR “scandentia”[MeSH Terms] OR “sirenia”[MeSH Terms] OR “xenarthra”[MeSH Terms] OR “haplorhini”[MeSH Terms:noexp] OR “strepsirhini”[MeSH Terms] OR “platyrrhini”[MeSH Terms] OR “tarsii”[MeSH Terms] OR “catarrhini”[MeSH Terms:noexp] OR “cercopithecidae”[MeSH Terms] OR “hylobatidae”[MeSH Terms] OR “hominidae”[MeSH Terms:noexp] OR “gorilla gorilla”[MeSH Terms] OR “pan paniscus”[MeSH Terms] OR “pan troglodytes”[MeSH Terms] OR “pongo pygmaeus”[MeSH Terms]) OR ((animals[tiab] OR animal[tiab] OR mice[Tiab] OR mus[Tiab] OR mouse[Tiab] OR murine[Tiab] OR woodmouse[tiab] OR rats[Tiab] OR rat[Tiab] OR murinae[Tiab] OR muridae[Tiab] OR cottonrat[tiab] OR cottonrats[tiab] OR hamster[tiab] OR hamsters[tiab] OR cricetinae[tiab] OR rodentia[Tiab] OR rodent[Tiab] OR rodents[Tiab] OR pigs[Tiab] OR pig[Tiab] OR swine[tiab] OR swines[tiab] OR piglets[tiab] OR piglet[tiab] OR boar[tiab] OR boars[tiab] OR “sus scrofa”[tiab] OR ferrets[tiab] OR ferret[tiab] OR polecat[tiab] OR polecats[tiab] OR “mustela putorius”[tiab] OR “guinea pigs”[Tiab] OR “guinea pig”[Tiab] OR cavia[Tiab] OR callithrix[Tiab] OR marmoset[Tiab] OR marmosets[Tiab] OR cebuella[Tiab] OR hapale[Tiab] OR octodon[Tiab] OR chinchilla[Tiab] OR chinchillas[Tiab] OR gerbillinae[Tiab] OR gerbil[Tiab] OR gerbils[Tiab] OR jird[Tiab] OR jirds[Tiab] OR merione[Tiab] OR meriones[Tiab] OR rabbits[Tiab] OR rabbit[Tiab] OR hares[Tiab] OR hare[Tiab] OR diptera[Tiab] OR flies[Tiab] OR fly[Tiab] OR dipteral[Tiab] OR drosophila[Tiab] OR drosophilidae[Tiab] OR cats[Tiab] OR cat[Tiab] OR carus[Tiab] OR felis[Tiab] OR nematoda[Tiab] OR nematode[Tiab] OR nematodes[Tiab] OR sipunculida[Tiab] OR dogs[Tiab] OR dog[Tiab] OR canine[Tiab] OR canines[Tiab] OR canis[Tiab] OR sheep[Tiab] OR sheeps[Tiab] OR mouflon[Tiab] OR mouflons[Tiab] OR ovis[Tiab] OR goats[Tiab] OR goat[Tiab] OR capra[Tiab] OR capras[Tiab] OR rupicapra[Tiab] OR rupicapras[Tiab] OR chamois[Tiab] OR haplorhini[Tiab] OR monkey[Tiab] OR monkeys[Tiab] OR anthropoidea[Tiab] OR anthropoids[Tiab] OR saguinus[Tiab] OR tamarin[Tiab] OR tamarins[Tiab] OR leontopithecus[Tiab] OR hominidae[Tiab] OR ape[Tiab] OR apes[Tiab] OR “pan paniscus”[Tiab] OR bonobo[Tiab] OR bonobos[Tiab] OR “pan troglodytes”[Tiab] OR gibbon[Tiab] OR gibbons[Tiab] OR siamang[Tiab] OR siamangs[Tiab] OR nomascus[Tiab] OR symphalangus[Tiab] OR chimpanzee[Tiab] OR chimpanzees[Tiab] OR prosimian[Tiab] OR prosimians[Tiab] OR “bush baby”[Tiab] OR bush babies[Tiab] OR galagos[Tiab] OR galago[Tiab] OR pongidae[Tiab] OR gorilla[Tiab] OR gorillas[Tiab] OR “pongo pygmaeus”[Tiab] OR orangutan[Tiab] OR orangutans[Tiab] OR lemur[Tiab] OR lemurs[Tiab] OR lemuridae[Tiab] OR horse[Tiab] OR horses[Tiab] OR equus[Tiab] OR cow[Tiab] OR calf[Tiab] OR bull[Tiab] OR chicken[Tiab] OR chickens[Tiab] OR gallus[Tiab] OR quail[Tiab] OR bird[Tiab] OR birds[Tiab] OR quails[Tiab] OR poultry[Tiab] OR poultries[Tiab] OR fowl[Tiab] OR fowls[Tiab] OR reptile[Tiab] OR reptilia[Tiab] OR reptiles[Tiab] OR snakes[Tiab] OR snake[Tiab] OR lizard[Tiab] OR lizards[Tiab] OR alligator[Tiab] OR alligators[Tiab] OR crocodile[Tiab] OR crocodiles[Tiab] OR turtle[Tiab] OR turtles[Tiab] OR amphibian[Tiab] OR amphibians[Tiab] OR amphibia[Tiab] OR frog[Tiab] OR frogs[Tiab] OR bombina[Tiab] OR salientia[Tiab] OR toad[Tiab] OR toads[Tiab] OR “epidalea calamita”[Tiab] OR salamander[Tiab] OR salamanders[Tiab] OR eel[Tiab] OR eels[Tiab] OR fish[Tiab] OR fishes[Tiab] OR pisces[Tiab] OR catfish[Tiab] OR catfishes[Tiab] OR siluriformes[Tiab] OR arius[Tiab] OR heteropneustes[Tiab] OR sheatfish[Tiab] OR perch[Tiab] OR perches[Tiab] OR percidae[Tiab] OR perca[Tiab] OR trout[Tiab] OR trouts[Tiab] OR char[Tiab] OR chars[Tiab] OR salvelinus[Tiab] OR minnow[Tiab] OR cyprinidae[Tiab] OR carps[Tiab] OR carp[Tiab] OR zebrafish[Tiab] OR zebrafishes[Tiab] OR goldfish[Tiab] OR goldfishes[Tiab] OR guppy[Tiab] OR guppies[Tiab] OR chub[Tiab] OR chubs[Tiab] OR tinca[Tiab] OR barbels[Tiab] OR barbus[Tiab] OR pimephales[Tiab] OR promelas[Tiab] OR “poecilia reticulata”[Tiab] OR mullet[Tiab] OR mullets[Tiab] OR eel[Tiab] OR eels[Tiab] OR seahorse[Tiab] OR seahorses[Tiab] OR mugil curema[Tiab] OR atlantic cod[Tiab] OR shark[Tiab] OR sharks[Tiab] OR catshark[Tiab] OR anguilla[Tiab] OR salmonid[Tiab] OR salmonids[Tiab] OR whitefish[Tiab] OR whitefishes[Tiab] OR salmon[Tiab] OR salmons[Tiab] OR sole[Tiab] OR solea[Tiab] OR lamprey[Tiab] OR lampreys[Tiab] OR pumpkinseed[Tiab] OR sunfish[Tiab] OR sunfishes[Tiab] OR tilapia[Tiab] OR tilapias[Tiab] OR turbot[Tiab] OR turbots[Tiab] OR flatfish[Tiab] OR flatfishes[Tiab] OR sciuridae[Tiab] OR squirrel[Tiab] OR squirrels[Tiab] OR chipmunk[Tiab] OR chipmunks[Tiab] OR suslik[Tiab] OR susliks[Tiab] OR vole[Tiab] OR voles[Tiab] OR lemming[Tiab] OR lemmings[Tiab] OR muskrat[Tiab] OR muskrats[Tiab] OR lemmus[Tiab] OR otter[Tiab] OR otters[Tiab] OR marten[Tiab] OR martens[Tiab] OR martes[Tiab] OR weasel[Tiab] OR badger[Tiab] OR badgers[Tiab] OR ermine[Tiab] OR mink[Tiab] OR minks[Tiab] OR sable[Tiab] OR sables[Tiab] OR gulo[Tiab] OR gulos[Tiab] OR wolverine[Tiab] OR wolverines[Tiab] OR mustela[Tiab] OR llama[Tiab] OR llamas[Tiab] OR alpaca[Tiab] OR alpacas[Tiab] OR camelid[Tiab] OR camelids[Tiab] OR guanaco[Tiab] OR guanacos[Tiab] OR chiroptera[Tiab] OR chiropteras[Tiab] OR bat[Tiab] OR bats[Tiab] OR fox[Tiab] OR foxes[Tiab] OR iguana[Tiab] OR iguanas[Tiab] OR xenopus laevis[Tiab] OR parakeet[Tiab] OR parakeets[Tiab] OR parrot[Tiab] OR parrots[Tiab] OR donkey[Tiab] OR donkeys[Tiab] OR mule[Tiab] OR mules[Tiab] OR zebra[Tiab] OR zebras[Tiab] OR shrew[Tiab] OR shrews[Tiab] OR bison[Tiab] OR bisons[Tiab] OR buffalo[Tiab] OR buffaloes[Tiab] OR deer[Tiab] OR deers[Tiab] OR bear[Tiab] OR bears[Tiab] OR panda[Tiab] OR pandas[Tiab] OR “wild hog”[Tiab] OR “wild boar”[Tiab] OR fitchew[Tiab] OR fitch[Tiab] OR beaver[Tiab] OR beavers[Tiab] OR jerboa[Tiab] OR jerboas[Tiab] OR capybara[Tiab] OR capybaras[Tiab]) NOT medline[sb]) | 1/7/2015: 5,723,242 1/14/2016 update: 209,076
# 2 Neurological Outcomes | Nervous system[mh] OR Nervous system physiological processes[mh] OR nervous-system[tiab] OR central-nervous[tiab] OR brain[tiab] OR blood-brain[tiab] OR brain-stem[tiab] OR cerebral[tiab] OR cortical[tiab] OR limbic OR amygdala OR hippocamp*[tiab] OR hypothalamus[tiab] OR parahippocamp*[tiab] OR perforant[tiab] OR mesencephalon OR prosencephalon OR rhombencephalon OR meninges OR dura-matter[tiab] OR spinal- cord[tiab] OR ganglia[tiab] OR ganglion[tiab] OR nerve[tiab] OR nervous[tiab] OR neural[tiab] OR neural-tube[tiab] OR afferent[tiab] OR auditory[tiab] OR olfactory[tiab] OR oculomotor [tiab] OR optic[tiab] OR retinal[tiab] OR efferent[tiab] OR perforant[tiab] OR neuroglia*[tiab] OR astrocyte*[tiab] OR microglia*[tiab] OR schwann-cell*[tiab] OR “myelin sheath”[tiab] OR neuron*[tiab] OR axon*[tiab] OR dendrit*[tiab] OR interneuron*[tiab] OR lewy- bod*[tiab] OR neurofibril*[tiab] OR purkinje-cell*[tiab] OR pyramidal-cell*[tiab] OR serotonergic[tiab] OR neuromuscular[tiab] OR neuroendocrine[tiab] OR neurosecret*[tiab] OR pituitary[tiab] OR pineal[tiab] OR synapse*[tiab] OR synaptic[tiab] OR presynaptic[tiab] OR postsynaptic[tiab] OR plasticity[tiab] OR hearing[tiab] OR vision[tiab] OR taste[tiab] OR smell[tiab] OR propriocept*[tiab] OR Nervous system diseases[mh] OR neurologic*[tiab] OR autonomic-nervous[tiab] OR central- nervous[tiab] OR demyelinat*[tiab] OR multiple-sclerosis[tiab] OR myasthenia-gravis[tiab] OR epilep*[tiab] OR encephalitis[tiab] OR meningitis[tiab] OR chronic-fatigue[tiab] OR dyskinesia*[tiab] OR dyston*[tiab] OR parkinson*[tiab] OR mobility[tiab] OR motor-control[tiab] OR motor-abilit*[tiab] OR motor-skill*[tiab] OR cranial- nerve[tiab] OR huntington*[tiab] OR tourette*[tiab] OR ataxia[tiab] OR hydranencephaly[tiab] OR neurofibra*[tiab] OR tauopath*[tiab] OR fibromyalgia[tiab] OR myopath*[tiab] OR neurodegenerat*[tiab] OR neuroimmunomodulat*[tiab] OR neuromuscular[tiab] OR neuropath*[tiab] OR neurosecret*[tiab] OR neurotox*[tiab] OR neurobehav*[tiab] OR dyslexi*[tiab] OR cognitive[tiab] OR cognition[tiab] OR intellect*[tiab] OR intelligence[tiab] OR mental- deficienc*[tiab] OR mental-deficit*[tiab] OR down-syndrome[tiab] OR rett-syndrome[tiab] OR memory-deficit*[tiab] OR memory- impair*[tiab] OR memory-loss*[tiab] OR Mental disorders[mh] OR Developmental disabilities[mh] OR developmental-delay*[tiab] OR developmental-disabilit*[tiab] OR anxiety[tiab] OR obsessive- compulsive[tiab] OR phobia*[tiab] OR phobic[tiab] OR antisocial[tiab] OR personality[tiab] OR schizophrenia[tiab] OR behavior[tiab] OR paranoid[tiab] OR paranoia[tiab] OR dementia[tiab] OR senile[tiab] OR senility[tiab] OR alzheimer[tiab] OR learning[tiab] OR aphasia[tiab] OR autism[tiab] OR autistic[tiab] OR attention-deficit[tiab] | 1/7/2015: 5,326,936 1/14/2016 update: 276,401
# 3 Fluoride | 1/7/2015: (Fluorides[mh:noexp] OR fluorides, topical[mh] OR sodium fluoride[mh] OR fluorid*[tiab] OR flurid*[tiab] OR fluorin*[tiab] OR florin*[tiab]) NOT (f-labeled[tiab] OR “fluorine- 18”[tiab] OR imaging[tiab] OR radioligand*[tiab]) 1/14/2016 update: (Fluorides[mh:noexp] OR fluorides, topical[mh] OR sodium fluoride[mh] OR fluorid*[tiab] OR flurid*[tiab] OR fluorin*[tiab] OR florin*[tiab]) NOT (18F[tiab] OR f-18[tiab] OR 19F[tiab] OR f-19[tiab] OR f-labeled[tiab] OR “fluorine-18”[tiab] OR “fluorine-19”[tiab] OR pet-scan[tiab] OR imaging[tiab] OR radioligand*[tiab]) Sort by: PublicationDate Filters: Publication date from 2015/01/01 to 2016/12/31 | 1/7/2015: 58,732 1/14/2016 update: 2813

## A.5 SCOPUS

Table A-5 Search Strategy for SCOPUS

Search ID | Search Terms | Date: Number of Records
# 4 | #1 AND #2 AND #3 | 1/7/2015: 1759 1/14/2016 update: 89
# 1 Animal Studies | TITLE-ABS (animal* OR mice OR mus OR mouse OR murine OR rats OR rat OR murinae OR muridae OR “cotton rat” OR “cotton rats” OR hamster* OR criceticae OR rodent* OR pigs OR pig OR swine* OR piglet* OR “guinea pigs” OR “guinea pig” OR cavia OR callithrix OR marmoset* OR cebuella OR hapale OR octodon OR chinchilla* OR gerbillinae OR gerbil* OR rabbit* OR hares OR hare OR cats OR cat OR carus OR felis OR dogs OR dog OR canine* OR canis OR sheep* OR mouflon* OR ovis OR goat* OR capra OR haplorhini OR monkey* OR anthropoid* OR saguinus OR tamarin* OR leontopithecus OR hominidae OR ape OR apes OR “pan paniscus” OR bonobo* OR “pan troglodytes” OR gibbon* OR nomascus OR symphalangus OR chimpanzee* OR prosimian* OR pongidae OR gorilla* OR “pongo pygmaeus” OR orangutan* OR lemur* OR lemuridae OR horse* OR equus OR cow OR calf OR bull OR chicken* OR gallus OR quail* OR bird OR birds OR poultry OR fowl OR fowls OR reptil* OR snake* OR lizard* OR turtle* OR amphibia* OR frog* OR xenopus OR bombina OR salientia OR toad* OR “epidalea calamita” OR salamander* OR fish OR fishes OR pisces OR catfish OR perch OR percidae OR perca OR trout OR char OR salmon OR salvelinus OR minnow* OR cyprinidae OR carp OR zebrafish OR “zebra fish” OR nematode* OR elegans OR diptera OR flies OR dipteral OR drosophil* OR squirrel* OR chipmunk* OR bear OR bears OR ursidae OR dolphin* OR porpoise* OR whale* OR cetacea) | 1/7/2015: 5,159,982 1/14/2016 update: 214,886
# 2 Neurological Outcomes | TITLE-ABS (“nervous system” OR “central-nervous” OR brain OR blood-brain OR brain-stem OR cerebral OR cortical OR limbic OR amygdala OR hippocamp* OR hypothalamus OR parahippocamp* OR perforant OR mesencephalon OR prosencephalon OR rhombencephalon OR meninges OR dura-matter OR spinal-cord OR ganglia OR ganglion OR nerve OR nervous OR neural OR neural-tube OR afferent OR auditory OR olfactory OR oculomotor OR optic OR retinal OR efferent OR perforant OR neuroglia* OR astrocyte* OR microglia* OR schwann-cell* OR “myelin sheath” OR neuron* OR axon* OR dendrit* OR interneuron* OR lewy-bod* OR neurofibril* OR purkinje-cell* OR pyramidal-cell* OR serotonergic OR neuromuscular OR neuroendocrine OR neurosecret* OR pituitary OR pineal OR synapse* OR synaptic OR presynaptic OR postsynaptic OR plasticity OR hearing OR vision OR taste OR smell OR propriocept* OR Nervous system diseases OR neurologic* OR autonomic-nervous OR central- nervous OR demyelinat* OR multiple-sclerosis OR myasthenia-gravis OR epilep* OR encephalitis OR meningitis OR chronic-fatigue OR dyskinesia* OR dyston* OR parkinson* OR mobility OR motor-control OR motor-abilit* OR motor-skill* OR cranial-nerve OR huntington* OR tourette* OR ataxia OR hydranencephaly OR neurofibra* OR tauopath* OR fibromyalgia OR myopath* OR neurodegenerat* OR neuroimmunomodulat* OR neuromuscular OR neuropath* OR neurosecret* OR neurotox* OR neurobehav* OR dyslexi* OR cognitive OR cognition OR intellect* OR intelligence OR mental- deficienc* OR mental-deficit* OR down-syndrome OR rett-syndrome OR memory-deficit* OR memory-impair* OR memory-loss* OR Mental disorders OR Developmental disabilities OR developmental- delay* OR developmental-disabilit* OR anxiety OR obsessive- compulsive OR phobia* OR phobic OR antisocial OR personality OR schizophrenia OR behavior OR paranoid OR paranoia OR dementia OR senile OR senility OR alzheimer OR learning OR aphasia OR autism OR autistic OR attention-deficit) | 1/7/2015: 7,558,830 1/14/2016 update: 453,341
# 3 Fluoride | 1/7/2015: TITLE-ABS ((fluorid* OR flurid* OR fluorin* OR florin*) AND NOT (f-labeled OR fluorine-18 OR imaging OR radioligand*))1/14/2016 update: TITLE-ABS(fluorid* OR flurid* OR fluorin* OR florin* OR fluorosis) AND NOT (18F OR F-18 OR “fluorine-18” OR 19F OR F-19 OR “fluorine-19” OR (PET AND scan) OR f-labeled OR imaging OR radioligand*) AND PUBYEAR>2014 | 1/7/2015: 153,560 1/14/2016 update: 7895

## A.6 Web of Science

Search Note: Searched 1/7/2015.

Table A-6 Search Strategy for Web of Science

Search ID | Search Terms | Date: Number of Records
# 4 | #1 AND #2 AND #3 Indexes=SCI-EXPANDED, SSCI, CPCI-S, CPCI-SSH, BKCI-S, BKCI-SSH, CCR-EXPANDED, | 1/7/2015: 1,836 1/14/2016 update: 59
# 1 Animal Studies | TOPIC: (“animal model” OR “animal models” OR “invertebrates” OR “chordata” OR “vertebrates” OR “amphibians” OR “birds” OR “fishes” OR “reptiles” OR “mammals” OR “primates” OR “artiodactyla” OR “carnivora” OR “cetacea” OR “chiroptera” OR “elephants” OR “hyraxes” OR “insectivora” OR “lagomorpha” OR “marsupialia” OR “monotremata” OR “perissodactyla” OR “rodentia” OR “scandentia” OR “sirenia” OR “xenarthra” OR “haplorhini” OR “strepsirhini” OR “platyrrhini” OR “tarsii” OR “catarrhini” OR “cercopithecidae” OR “hylobatidae” OR “hominidae” OR “gorilla” OR “pan paniscus” OR “pan troglodytes” OR “pongo pygmaeus” OR animals OR animal OR mice OR mus OR mouse OR murine OR woodmouse OR rats OR rat OR murinae OR muridae OR cottonrat OR cottonrats OR hamster OR hamsters OR cricetinae OR rodentia OR rodent OR rodents OR pigs OR pig OR swine OR swines OR piglets OR piglet OR boar OR boars OR “sus scrofa” OR ferrets OR ferret OR polecat OR polecats OR “mustela putorius” OR “guinea pigs” OR “guinea pig” OR cavia OR callithrix OR marmoset OR marmosets OR cebuella OR hapale OR octodon OR chinchilla OR chinchillas OR gerbillinae OR gerbil OR gerbils OR jird OR jirds OR merione OR meriones OR rabbits OR rabbit OR hares OR hare OR diptera OR flies OR fly OR dipteral OR drosophila OR drosophilidae OR cats OR cat OR carus OR felis OR nematoda OR nematode OR nematodes OR sipunculida OR dogs OR dog OR canine OR canines OR canis OR sheep OR sheeps OR mouflon OR mouflons OR ovis OR goats OR goat OR capra OR capras OR rupicapra OR rupicapras OR chamois OR haplorhini OR monkey OR monkeys OR anthropoidea OR anthropoids OR saguinus OR tamarin OR tamarins OR leontopithecus OR hominidae OR ape OR apes OR “pan paniscus” OR bonobo OR bonobos OR “pan troglodytes” OR gibbon OR gibbons OR siamang OR siamangs OR nomascus OR symphalangus OR chimpanzee OR chimpanzees OR prosimian OR prosimians OR “bush baby” OR bush babies OR galagos OR galago OR pongidae OR gorilla OR gorillas OR “pongo pygmaeus” OR orangutan OR orangutans OR lemur OR lemurs OR lemuridae OR horse OR horses OR equus OR cow OR calf OR bull OR chicken OR chickens OR gallus OR quail OR bird OR birds OR quails OR poultry OR poultries OR fowl OR fowls OR reptile OR reptilia OR reptiles OR snakes OR snake OR lizard OR lizards OR alligator OR alligators OR crocodile OR crocodiles OR turtle OR turtles OR amphibian OR amphibians OR amphibia OR frog OR frogs OR bombina OR salientia OR toad OR toads OR “epidalea calamita” OR salamander OR salamanders OR eel OR eels OR fish OR fishes OR pisces OR catfish OR catfishes OR siluriformes OR arius OR heteropneustes OR sheatfish OR perch OR perches OR percidae OR perca OR trout OR trouts OR char OR chars OR salvelinus OR minnow OR cyprinidae OR carps OR carp OR zebrafish OR zebrafishes OR goldfish OR goldfishes OR guppy OR guppies OR chub OR chubs OR tinca OR barbels OR barbus OR pimephales OR promelas OR “poecilia reticulata” OR mullet OR mullets OR eel OR eels OR seahorse OR seahorses OR mugil curema OR atlantic cod OR shark OR sharks OR catshark OR anguilla OR salmonid OR salmonids OR whitefish OR whitefishes OR salmon OR salmons OR sole OR solea OR lamprey OR lampreys OR pumpkinseed OR sunfish OR sunfishes OR tilapia OR tilapias OR turbot OR turbots OR flatfish OR flatfishes OR sciuridae OR squirrel OR squirrels OR chipmunk OR chipmunks OR suslik OR susliks OR vole OR voles OR lemming OR lemmings OR muskrat OR muskrats OR lemmus OR otter OR otters OR marten OR martens OR martes OR weasel OR badger OR badgers OR ermine OR mink OR minks OR sable OR sables OR gulo OR gulos OR wolverine OR wolverines OR mustela OR llama OR llamas OR alpaca OR alpacas OR camelid OR camelids OR guanaco OR guanacos OR chiroptera OR chiropteras OR bat OR bats OR fox OR foxes OR iguana OR iguanas OR xenopus laevis OR parakeet OR parakeets OR parrot OR parrots OR donkey OR donkeys OR mule OR mules OR zebra OR zebras OR shrew OR shrews OR bison OR bisons OR buffalo OR buffaloes OR deer OR deers OR bear OR bears OR panda OR pandas OR “wild hog” OR “wild boar” OR fitchew OR fitch OR beaver OR beavers OR jerboa OR jerboas OR capybara OR capybaras) Indexes=SCI-EXPANDED, SSCI, CPCI-S, CPCI-SSH, BKCI-S, BKCI-SSH, CCR-EXPANDED, | 1/7/2015: 5,945,667 1/14/2016 update: 248,464
# 2 Neurolog-ical outcomes | TOPIC: (“nervous system” OR “central-nervous” OR brain OR blood- brain OR brain-stem OR cerebral OR cortical OR limbic OR amygdala OR hippocamp* OR hypothalamus OR parahippocamp* OR perforant OR mesencephalon OR prosencephalon OR rhombencephalon OR meninges OR dura-matter OR spinal-cord OR ganglia OR ganglion OR nerve OR nervous OR neural OR neural-tube OR afferent OR auditory OR olfactory OR oculomotor OR optic OR retinal OR efferent OR perforant OR neuroglia* OR astrocyte* OR microglia* OR schwann- cell* OR “myelin sheath” OR neuron* OR axon* OR dendrit* OR interneuron* OR lewy-bod* OR neurofibril* OR purkinje-cell* OR pyramidal-cell* OR serotonergic OR neuromuscular OR neuroendocrine OR neurosecret* OR pituitary OR pineal OR synapse* OR synaptic OR presynaptic OR postsynaptic OR plasticity OR hearing OR vision OR taste OR smell OR propriocept* OR Nervous system diseases OR neurologic* OR autonomic-nervous OR central- nervous OR demyelinat* OR multiple-sclerosis OR myasthenia-gravis OR epilep* OR encephalitis OR meningitis OR chronic-fatigue OR dyskinesia* OR dyston* OR parkinson* OR mobility OR motor-control OR motor-abilit* OR motor-skill* OR cranial-nerve OR huntington* OR tourette* OR ataxia OR hydranencephaly OR neurofibra* OR tauopath* OR fibromyalgia OR myopath* OR neurodegenerat* OR neuroimmunomodulat* OR neuromuscular OR neuropath* OR neurosecret* OR neurotox* OR neurobehav* OR dyslexi* OR cognitive OR cognition OR intellect* OR intelligence OR mental- deficienc* OR mental-deficit* OR down-syndrome OR rett-syndrome OR memory-deficit* OR memory-impair* OR memory-loss* OR Mental disorders OR Developmental disabilities OR developmental- delay* OR developmental-disabilit* OR anxiety OR obsessive- compulsive OR phobia* OR phobic OR antisocial OR personality OR schizophrenia OR behavior OR paranoid OR paranoia OR dementia OR senile OR senility OR alzheimer OR learning OR aphasia OR autism OR autistic OR attention-deficit) Indexes=SCI-EXPANDED, SSCI, CPCI-S, CPCI-SSH, BKCI-S, BKCI-SSH, CCR-EXPANDED, | 1/7/2015: 7,065,701 1/14/2016 update: 419,568
# 3 Fluoride | 1/7/2015: TOPIC: ((fluorid* OR flurid* OR fluorin* OR florin*) NOT (f-labeled OR “fluorine-18” OR imaging OR radioligand*)) Indexes=SCI-EXPANDED, SSCI, CPCI-S, CPCI-SSH, BKCI-S, BKCI-SSH, CCR-EXPANDED1/14/2016 update: TI=(fluorid* OR flurid* OR fluorin* OR florin* OR fluorosis) NOT TS=((18F OR F-18 OR “fluorine-18” OR 19F OR F-19 OR “fluorine-19” OR (PET AND scan) OR f-labeled OR imaging OR radioligand*)) Indexes=SCI-EXPANDED, SSCI, CPCI-S, CPCI-SSH, BKCI-S, BKCI-SSH, CCR- | 1/7/2015: 147,851 1/14/2016 update: 2551