# 7 Evidence Integration

## Introduction

The last step in the cancer hazard evaluation process (Figure 7-1) is to integrate the evidence from the cancer studies in humans and animals with the evidence from mechanistic and other relevant data and apply the Report on Carcinogens (RoC) listing criteria to reach a preliminary listing recommendation. This step is usually captured in the final section of the RoC monograph. Guidelines for integrating evidence across studies of the same evidence stream to reach a level-of-evidence conclusion (LoE) are discussed in the relevant sections of the handbook:

- Human cancer epidemiology studies (see Section 3)
  - LoE: Sufficient, limited, or inadequate
- Animal cancer studies (see Section 4)
  - LoE: Sufficient, not sufficient
- Mechanistic studies (see Section 6)
  - LoE: Convincing, supporting

Section 7 brings forward these assessments and provides guidance for integrating the collective body of evidence as a unit (rather than focusing on individual studies).

Figure 7-1

Cancer Hazard Evaluation Process

A substance (agent, substance, mixture, or exposure circumstance or scenario) is listed in the RoC as either known or reasonably anticipated to be a human carcinogen. The listing recommendation is reached by applying the RoC criteria to the cancer hazard assessment (see Box 7-1). Historically, the RoC criteria have been informed by and overlap with (but are not the same as) the IARC criteria for carcinogen classifications (IARC 2019). Substances not meeting these criteria are not listed in the RoC and the review is captured in an RoC appendix.

Box 7-1 Summary of Report on Carcinogens Listing Criteria

Known to be a human carcinogen

- Sufficient evidence of carcinogenicity from studies in humans*

Reasonably anticipated to be a human carcinogen

Meets one of the following:

- Limited evidence of carcinogenicity from studies in humans*
- Sufficient evidence of carcinogenicity from studies in experimental animals
- The substance belongs to a structurally related class of substances that are listed in the RoC
- Convincing relevant information that the agent acts through a mechanism indicating that it would likely cause cancer in humans

*Evidence from studies in humans includes cancer epidemiology studies, or mechanistic studies in exposed humans, or both.

Source: NTP (2023).

Conclusions regarding the carcinogenicity of a substance are based on scientific judgment, considering all relevant data. The listing categories reflect the strength of the evidence or the confidence for these conclusions.

Since the publication of the 2015 Handbook for Preparing RoC Monographs (NTP 2015), the RoC Group has developed more transparent, multistep approaches to integrate the evidence across data streams and evaluate its coherence (Section 7.3) and guidance on how the LoE of carcinogenicity from each evidence stream translates to the overall listing recommendation (Section 7.2). Coherence is defined as when the evidence across streams (e.g., human cancer, mechanistic, and animals) is consistent, forms a united whole, and tells a cohesive story of causality.

## 7.1 Considerations and Approaches

In evaluating causality, we are cognizant that many factors contribute to cancer hazards and the importance of effect modifiers. Many environmental causes of cancer are neither necessary nor sufficient in the absence of other factors to produce the disease; however, a cause does not have to be either necessary or sufficient for its removal to decrease disease incidence (Rothman and Greenland 2005).

In reaching our listing decisions, we use triangulation approaches, considering Hill’s and other causality principles to integrate the evidence across evidence streams. Triangulation refers to integrating evidence from different research or methodological approaches, each of which have different but unrelated sources of potential bias (Lawlor et al. 2016).

### 7.1.1 Bradford Hill’s Considerations of Causality

Bradford Hill published his viewpoints on causality as considerations for determining whether the evidence from observational epidemiological studies is causal (Bradford Hill 1965). His level-of-evidence conclusions from human studies focused on the strength of the association, consistency across studies, evidence of an exposure-response gradient, and temporality of exposure. For evidence integration, we collectively consider and concentrate on the following Bradford Hill factors: strength and consistency across evidence streams, biological plausibility and coherence, and temporality. (Analogy and specificity are less relevant, and we are integrating experimental data). Strong LoE conclusions (e.g., sufficient from human or animal cancer studies, convincing from mechanistic studies) in more than one evidence stream (consistency) increases the strength of the hazard evaluation classification. Table 7-1 provides examples of evaluations showing evidence concordance between human, toxicological, and mechanistic evidence; the mechanistic studies provide biological plausibility that the association between the exposure and outcome are causal and consistent with biological knowledge.

Table 7-1 Selected Examples of Coherence Biological Plausibility, and Consistency across Evidence Streams

Substance | Toxicological/ Mechanistic Evidence^a^ | Epidemiological Evidence
TCE Known human carcinogens | Metabolism and mechanistic studies show that GSH pathway is important in TCE-induced kidney carcinogenicity • Cytotoxic and mutagenic metabolites are formed in or transported to the kidney | A case-control study found an increased risk of kidney cancer among individuals who had genes that produced enzymes involved in GSH but not in individuals without functional genes
NSW High confidence for a causal relationship with human cancer | Biological understanding, animal cancer studies, and human mechanistic studies | Epidemiological studies found higher breast cancer risk in women for:
NSW High confidence for a causal relationship with human cancer | • Breast cancer biology: higher susceptibility to cancer at different stages of development (prenatal life, infancy, puberty, early adulthood, and timing of first pregnancy) | • Starting NSW at a younger age in adulthood
NSW High confidence for a causal relationship with human cancer | • Simulated night shift work promotes human breast tumors/cells implanted into rodents | • Recency of exposure
NSW High confidence for a causal relationship with human cancer | • Increased estrogen levels associated with night shift work | • Hormone-receptor positive tumors

Sources: NTP (2021a; 2021h).

TCE = trichloroethylene; GSH = glutathione conjugation; NSW = night shift work.

^a^ All evidence types (exposed humans, animal models, in vitro).

### 7.1.2 Other Considerations

For some evaluations, substance-specific guidance may be available. Specific lines of evidence from human mechanistic studies were critical in informing the evidence of cancer epidemiology studies of viruses (NTP 2021i). For instance, many epidemiological studies on viruses include cross-sectional exposure assessment (e.g., measured viral antibodies to the virus at the same time as cancer assessment) and findings of monoclonality in cancer cells can help provide evidence of temporality (e.g., suggest that infections take place prior to tumor formation). Several virus experts noted that strict application of the Hill factors was challenging when assessing the cancer evidence for some viruses and developed additional factors to consider when evaluating causality. In the RoC review of several viruses, we synthesized published guidelines from virus experts to guide the cancer hazard evaluation (NTP 2021i).

### 7.1.3 Evaluating the Coherence of the Evidence: Triangulation Approaches and Evidence-based Tables

To increase transparency and facilitate the overall cancer hazard evaluation, we use a stepwise approach to integrate the evidence across evidence streams. This approach has several advantages: (1) It compiles and brings forward the assessment conclusions from each evidence stream. (2) It uses triangulation approaches to assess the evidence that may have different biases across the different streams. (3) It provides relevant information from each evidence stream to evaluate the coherence of the database. (4) It encompasses a series of tables, with increasing levels of integration, enhancing the transparency of the rationale for our conclusion. (5) It facilitates defining or contextualizing the hazard (if relevant) or identifying research gaps.

Triangulation aims to integrate data from different methodological approaches with different biases, and to exploit these differences to draw qualitative conclusions. For health hazard assessments evaluating causality, triangulation can occur at multiple levels—within a single study, across studies of a specific evidence stream (human and animal cancer and mechanistic studies) or types (epidemiology, in vivo, in vitro) (NASEM 2022). The human cancer section considers the first two levels, whereas this section considers the last level.

The approach typically consists of three progressive steps or evidence-based tables and was informed by the NTP Cancer Assessment of Night Shift Work and Light at Night (NTP 2021a) (see Figure 7-2 for an example of three evidence-based tables and how each table informs subsequent tables).

Figure 7-2

Series of Progressive Evidence-Based Tables

The three-evidence-based tables are examples from the Light at Night evaluation and correspond to the three-step approach. Note that the entries for each data are only a subset of the evidence, see the Light at Night Cancer Hazard Assessment (NTP 2021a) and Table 7-4 and Table 7-5 for more complete entries of Steps 2 and 3. The purpose of the figure is to show the relationship between the three tables: Step 1 assessments inform Step 2 conclusions or Step 3 assessments. Step 2 assessment integrates the relevant evidence from multiple assessments (e.g., different evidence types) from Step 1. Step 3 overall evaluation integrates the evidence from relevant Step 1 and 2 assessments.

#### Step 1: Summarize the Assessments of the Collective Evidence for Each Data Stream

The first step in the evidence-integration process brings forward the assessments from each evidence stream, for example, each relevant entry (referred to as study set) in the overall cancer hazard EECO (evidence, exposure, comparison group, outcome/endpoint). For some evaluations, the “exposure” may be a proposed intermediate (e.g., circadian disruption). For each study set, the assessment summary presents the scope and type of evidence, the strengths and limitations of the database (e.g., most impactful bias across studies), and the key findings that may inform evidence concordance (see Table 7-2). Each assessment (e.g., study set) is based on a rigorous review of the consistency and informativeness of the individual studies (see Sections 3, 4, and 6). Here, the strength and limitations and triangulation approaches refer to the collective body of evidence for each study set and were informed by the individual study assessments. These evidence-based summary tables are also included in the relevant section and are brought forward to the evidence integration sections to increase the transparency of the overall evaluation. A human epidemiology study set typically consists of all studies (sometimes stratified by study design or other common characteristic) for a specific cancer site. Depending on the substance, an animal study set may be all studies for a specific tumor type or all tumors, models, or common tumors across similar chemicals. For mechanistic studies, the assessment summary is usually for an influential question (Step 2 for biological effects; see Section 6.4) rather than at the study set level (Step 1; see Section 6.4). Influential questions (as defined in 6.2.4) are the scientific issues that are: (1) critical for understanding cancer mechanisms and biological and human relevance and (2) will most likely impact the LoE conclusions (e.g., support or arguing against convincing).

Table 7-2 Template Example for Summarizing the Assessment of Each Evidence Stream

Exposure | Outcome | Evidence Streams | Strength and Limitations | Assessment
Substance | Cancer type | Number and type of human cancer studies Cohort studies Case-control studies Pooled or meta-analyses | Summary of the most influential biases (direction, magnitude, impact) across studies by study design or other relevant grouping | Consistency of findings and patterns for factors, such as exposure matrices and levels, cancer subtypes, effect modifiers
Substance | Cancer type or across multiple cancers | Number and type of animal cancer studies Animal models (e.g., route, species) | Summary of most influential biases (direction, magnitude, impact) across studies by model, route, or other relevant grouping | Exposure-related cancer sites, common cancer sites across groups of chemicals Information relevant to evidence integration
Substance | Biological effect example 1 | Number and type of mechanistic studies Model (e.g., in vitro, in vivo) Exposed humans | Summary of the most influential biases (direction, magnitude, impact) across studies and relevance of evidence type | Confidence judgment for influential question(s) Information relevant to evidence integration
Intermediate (Biomarker for Proposed Mechanism) | Cancer type | Number and type of cancer (human or animal) relevant studies | Summary of most influential biases (direction, magnitude, impact) across studies by relevant grouping | Consistency and patterns for factors, such as exposure matrices, cancer subtypes, effect modifiers

#### Step 2: Integrate the Mechanistic Evidence

Mechanistic data are often integrated across influential questions to reach LoE conclusions (see Section 6.4.3) or for a specific mechanism (e.g., reported or development of a mode of action [MoA]) before the overall evidence integration. Integration may be multifaceted: multiple evidence types for multiple exposure/outcome pairs (e.g., exposure to intermediate, intermediate to cancer). This step is conducted in the mechanistic section and the evidence is brought forward to Section 7 to provide transparency for the overall evaluation (see Section 6 for guidance on evaluation of the evidence.) Evidence-based tables describe the confidence in the evidence for each exposure/outcome pair or mechanistic question and overall assessment. Table 7-3 provides an example adapted from the light at night (LAN) evaluation of circadian disruption as a cancer mechanism. Notably, the mechanistic evaluation may go beyond an LoE conclusion and provide conclusions for specific facets of the evidence base (e.g., by evidence type). New to this handbook is guidance for evaluating the confidence for the evidence for biological effects and the overall LoE of carcinogenicity from mechanistic studies.

Table 7-3 Intermediate Tables on Specific Mechanisms: Light at Night Example

Exposure or Mechanism | Evidence Streams or Approach | Study Set Conclusions^a^ | Assessment
Circadian Disruption Melatonin Suppression | Molecular epidemiology studies measuring nocturnal urinary melatonin levels in night shift workers Some studies measured LAN and melatonin levels among shift workers Experimental studies of LAN and melatonin suppression in humans Experimental studies of LAN, melatonin suppression, and tumor promotion in animals Melatonin studies and cancer in humans and animals Experimental studies: in vivo or in vitro mechanistic studies | Strong evidence for melatonin suppression in night shift workers Database for melatonin suppression in shift work animal models is inadequate Strong evidence that electrical LAN exposure in people’s everyday lives (depending on the wavelength, level, duration, and photic history) can cause melatonin suppression Weak evidence that higher melatonin levels (or proxies) are related to decreased cancer incidence Strong evidence that melatonin can reduce tumor growth and for its oncostatic properties, which may protect from all biological effects considered to be hallmarks of cancer Oncostatic properties involve epigenetic mechanisms relevant to cancer, particularly breast cancer | Indirect evidence that melatonin suppression contributes to breast cancer development in night shift workers Strong evidence that melatonin suppression plays a role in LAN-induced breast carcinogenicity in experimental animals Data inadequate to evaluate whether LAN during night work contributes to cancer risk

Source: NTP (2021a).

LAN = light at night.

^a^ New to this handbook is formal guidance for reaching conclusions.

#### Step 3: Integrate the Evidence across All Streams

The final step in the assessment is to integrate all the relevant evidence and apply the RoC listing criteria to this assessment to reach a listing decision. Here we present the evidence-integration assessment, and Section 7.2 discusses applying the RoC listing criteria to that assessment. The overall cancer hazard evaluation uses triangulation approaches for integrating and assessing the coherence of the cancer (human and animal) and mechanistic assessments. Whereas triangulation approaches for epidemiological studies evaluate biases for individual studies (internal validity), triangulation approaches for the overall evidence evaluation consider general biases (identified limitations associated with specific evidence sources) for a collective body of evidence. For example, human cancer studies are the most relevant studies but can be subjected to biases both toward and away from the null due to their observational nature. Animal cancer studies are controlled exposure but are less human relevant, and mechanistic studies are not on the apical endpoint of interest. The strengths and limitations in Table 7-3 (discussed above in Step 2) and Table 7-4 can help facilitate evidence integration. Table 7-4 provides an example adapted from the LAN evaluation, which illustrates the integration of the conclusions for specific questions or datasets from each evidence stream. Each monograph would have similar tables and, when relevant, figures depicting the evidence integration.

Table 7-4 Overall Evidence-Integration: Light at Night and Cancer

Evidence Streams | Conclusion | Overall Integration
Human epidemiological studies of female breast cancer 5 studies of outdoor light 10 studies of light in the sleeping area Experimental animal studies Primarily initiation-promotion studies of continuous, dim, or interrupted light or bright, blue-enriched light during the day Mechanistic and biomonitoring data Melatonin suppression hypothesis Circadian disruption theory Biological effects associated with cancer | Inadequate evidence that LAN (indoor or outdoor) causes breast cancer risk Strong evidence from studies in experimental animals that exposure to LAN promotes implanted human breast cancer proliferation or growth and mouse mammary-gland tumor growth Bright, blue-enriched light during the day increased the level of nighttime melatonin levels and decreased tumor growth in experimental animals Strong evidence that melatonin suppression plays a role in LAN-induced breast carcinogenicity in experimental animals | Strong toxicological and mechanistic than data that exposure to LAN causes melatonin suppression and other types of circadian disruption, which leads to breast or mammary-gland cancer proliferation and growth in experimental animals LAN induces biological effects in experimental animals associated with: (1) carcinogenicity and (2) melatonin suppression and circadian clock gene deregulation Some of these biological effects are observed among night shift workers Exposure to excessive LAN can cause circadian disruption in humans

Source: NTP (2021a).

LAN = light at night.

## 7.2 Integrating Level-of-evidence Conclusions

New to the handbook are formal considerations for integrating the LoE conclusions of carcinogenicity from human cancer, experimental animal cancer, and mechanistic studies. These considerations were informed by previous RoC evaluations and the 2019 IARC preamble. Although not part of the listing criteria, RoC evaluations often use the term “supporting mechanism data” for evaluations that rely mainly on human or animal mechanistic evidence with data showing biological plausibility. Table 7-5 delineates how LoE from each evidence stream relates to each RoC criterion. The overall listing recommendation also considers the coherence of the body of evidence and all relevant information, as discussed in Section 7.2.

Table 7-5 Evidence-Integration Guidance Table^a^

RoC Criterion | Human Cancer Epidemiology | Animal Cancer | Mechanisms: Overall | Mechanisms: Exposed Humans | Listing^b^
Sufficient Evidence from Studies in Humans | Sufficient | Any^c^ | Any^c^ | Any^c^ | Known
Sufficient Evidence from Studies in Humans | Limited | Any^c^ | Supporting^d^ | Robust^e^ | Known
Limited Evidence from Studies in Humans | Limited | Any^c^ | Any^c^ | Not robust | RAHC
Limited Evidence from Studies in Humans | Inadequate | Not sufficient | Convincing | Robust^e^ | RAHC
Sufficient Evidence from Studies in Experimental Animals | Inadequate | Sufficient | Any^c^ | Any^c^ | RAHC
Biological Plausibility or Member of a Listed Class | Inadequate | Not sufficient | Convincing^e,f^ | Any^c^ | RAHC

RAHC = reasonably anticipated to be a human carcinogen.

^a^ Descriptors based on the RoC listing criteria and convention. Human cancer studies: sufficient, limited, inadequate (see Section 3); animal cancer studies: sufficient, not sufficient (see Section 4); mechanism: convincing, supporting (see Section 6).

^b^ Also considers the coherence of the database (see Section 7.2.2), which may be especially helpful for integrating human evidence from epidemiological and mechanistic but is not required.

^c^ Any indicates that the LoE for the evidence stream does not affect the cancer hazard conclusion (e.g., for animal cancer studies, it could be sufficient or not sufficient).

^d^ The LoE from mechanistic data depends in part on the human cancer epidemiology studies (e.g., limited evidence can range from bordering inadequate to bordering sufficient, and a similar range could be made for the strength of evidence from human mechanistic studies).

^e^ See Section 6.4.3, Confidence of the Evidence, informativeness of the study set.

^f^ Convincing can be from a mode of action, biological effects, or cancer predictions from clustering/read-across approaches.

### 7.2.1 Evaluations with Substantial Human and Animal Cancer Databases

The RoC listing criteria requires sufficient—credible association not reasonably explained by chance, bias, or confounding—evidence of carcinogenicity from studies in humans to list a substance as known to be a human carcinogen: the evidence demonstrates that the substance causes cancer. Typically, the evidence is from cancer epidemiological studies, but the RoC listing criteria specifies that human evidence also includes other types of studies, such as clinical and mechanistic studies in exposed humans. When the evidence from human cancer epidemiological studies is limited, a substance may be listed as known to be a human carcinogen if there is robust human mechanistic evidence (see Box 7-2 for an example of an RoC listing). The overall LoE of carcinogenicity from mechanistic studies can range from supporting (high) to convincing. Convincing mechanistic data are rarely only from human studies, as evidence in cancer models (e.g., in vivo or in vitro) provides context (e.g., proposed mechanisms or pathways for the biological effects) for the effects observed in humans. Current knowledge indicates that a substance would not typically be listed as known to be a human carcinogen with inadequate evidence from cancer epidemiological studies because: (1) cancer type often provides relevancy of the mechanistic data and (2) a second evidence stream increases the confidence for the cancer hazard classifications. Examples of notable exceptions include substance(s) that release radioactivity (e.g., neutrons) or are metabolized (e.g., dyes metabolized to benzidine) to a known human carcinogen.

Box 7-2 Cumene Example

Reasonably anticipated to be a human carcinogen

Exposure-related tumors in experimental animals:

- Rats: kidney (males)
- Mice: lung (both sexes), liver (males)

Human cancer epidemiology studies:

- Inadequate

Mechanistic data:

- Human relevance of male rat kidney tumors uncertain

Evidence integration:

- Sufficient LoE from studies in experimental animals: lung and liver tumors in mice
- Supporting mechanistic evidence for lung and liver tumors

Source: NTP (2021e).

Substances are listed as reasonably anticipated rather than known to be a human carcinogen when there is strong evidence but less confidence in it as reflected by the LoE from human studies (limited), less human-relevant evidence (e.g., sufficient from animal cancer studies), or less direct evidence (e.g., noncancer studies, convincing LoE from mechanistic studies) in the absence of human and animal cancer data.

Mechanistic evidence can increase or decrease the certainty of the evidence from cancer studies (e.g., limited LoE from human cancer studies to known human carcinogen discussed above for ethylene oxide). If there is compelling evidence that a tumor site observed in experimental animals occurs by a nonhuman relevant mechanism, that cancer site would not be included in the evidence for reaching an LoE conclusion from studies in experimental animals (see Box 7-3 for the cumene example). The nonhuman relevance MoA only applies to the targeted cancer site and not the overall evaluation.

Box 7-3 Ethylene Oxide Example

Known to be a human carcinogen

Limited evidence from cancer epidemiological studies:

- Lymphohematopoietic and breast cancer

Mechanistic evidence: Direct acting alkylating agent leading to adducts, mutation, and DNA and chromosomal damage:

- Genetic damage found in exposed workers and model systems

Evidence integration

- Human relevance of male rat kidney tumors uncertain

Evidence integration:

- Sufficient evidence from studies in humans: Human cancer epidemiological and mechanistic studies
- Sufficient evidence from studies in experimental animals: hematopoietic system and other sites

Source: NTP (2021g).

### 7.2.2 Limited Cancer Databases and Class Evaluations

The RoC criteria permit listing substance(s) with little or no cancer data in humans or experimental animals (see Section 6) as reasonably anticipated to be a human carcinogen if the evidence of carcinogenicity from mechanistic studies is convincing or if the substance is a member of a class whose members are listed in the RoC. Mechanistic data can also be used to list a substance as known with limited evidence from human cancer epidemiology studies. Moreover, the listing criteria note that cancer hazard conclusions (e.g., listing recommendations for known or reasonably anticipated to be a human carcinogen) “are based on scientific judgment with consideration given to all relevant information,” which occur during the assessment of mechanistic evidence (see Section 6.4.3) or overall cancer hazard evaluation. As of the 15th RoC, these criteria have been used primarily to list substance(s) metabolized to a listed carcinogen. The listing decision was reached by integrating mechanistic and metabolism evidence with cancer data of the listed carcinogen or any class members. The listing category for the substance under review (known or reasonably anticipated to be a human carcinogen) depends on the listed category of the metabolite and the evidence type (e.g., exposed humans, animal model) for the metabolism and mechanistic data. An example of another type of evidence that can be used to list substances as a class is a listing of similar substances that cause cancer by a common mechanism (e.g., cobalt compounds that release cobalt ion in vivo). In this handbook, we expand our assessment of chemicals by incorporating clustering and read-across approaches in our cancer hazard evaluations (see Section 6.5). Table 7-6 provides examples of how different types of evidence can be integrated to reach a listing decision.

Table 7-6 Selected Examples of Substances Listed with Little Cancer Data or Listed from Class Evaluations

Substance(s) | Mechanistic and Relevant Data | Cancer Data | Listing Category
Dyes Metabolized to Benzidine | Release free benzidine in exposed humans and other species Exposure to dyes is equivalent to exposure to equimolar doses of benzidine (exposed humans) | Benzidine is a known human carcinogen Three class members cause tumors in experimental animals | Known
Diazoaminobenzene (DAAB) | Metabolized to benzene (animals and human tissues) and is quantitatively similar to predicted benzene and aniline metabolites (animals)^a^ Causes genetic damage in animals and bacteria | Benzene is a known human carcinogen | RAHC
Cobalt and Cobalt Compounds That Release Cobalt Ions In Vivo | Cobalt ion largely responsible for toxicity and carcinogenicity Similar mechanisms regardless of water solubility (bioavailability and mechanistic studies) | Sufficient evidence of carcinogenicity for cobalt metal and several cobalt compounds from studies in experimental animals regardless of solubility | RAHC

RAHC = reasonably anticipated to be a human carcinogen.

Sources: NTP (2021c; 2021d; 2021f).

^a^ DAAB was listed as RAHC instead of known because the mechanistic data were not in exposed humans.

## 7.3 Supplementary Public Health Considerations

The Report on Carcinogens identifies and lists potential cancer hazards, as mandated by the Public Health Service Act in 1978. However, the RoC does not identify carcinogenic risks (including exposure assessment, dose-response analysis, and risk characterization), and therefore, is not, and should not be interpreted in the context of a risk assessment. Additionally, the document does not provide clinical guidance to individuals. Many factors, including the amount and duration of exposure and an individual’s susceptibility to a substance, affect whether a person will or will not develop cancer (NTP 2021b).

The RoC does provide a comprehensive, relevant, and broadly applicable set of cancer hazard evaluations for use in a variety of contexts to ultimately improve public health. As such, our aim is to tailor each evaluation, if possible, to most appropriately characterize and contextualize potential carcinogenic hazards under review in a manner that is data driven, interpretable, and translatable. The evidence-integration stage (within and across data streams) may inform how the hazard under review (e.g., the listing definition) is characterized. Occasionally, the target hazard definition for a given scenario may differ from the substance under review for listing the Report on Carcinogens. When there is compelling scientific evidence, the hazard or chemical class may be defined by a mechanism (e.g., release of cobalt ion [the carcinogenic species] via in vivo metabolism, circadian disruption) or by the human epidemiological evidence (e.g., persistent night shift work, consumption of alcoholic beverages). Contextualizing the hazard may help inform intervention strategies, especially for widespread exposure that is unlikely to be banned (e.g., night shift work). In the absence of compelling evidence, hazard identification is not usually restricted to the exposure conditions of the cancer studies. As we continue to improve the RoC, our goal is to increase the specificity of hazard characterization and the implications of our evaluations, if applicable and relevant. On a case-by-case basis, we aim to improve cancer hazard communication by providing information on interventions, health disparities, and sensitive populations (such as specific lifestages of development) as part of the overall cancer hazard evaluation and other relevant media (Lunn et al. 2022). We also hope to advance cancer hazard classification by identifying and elaborating on research gaps that may encourage future research.

## References

Bradford Hill A. 1965. The environment and disease: Association or causation? Proc R Soc Med. 58(5):295–300. 14283879
International Agency for Research on Cancer (IARC). 2019. Preamble to the IARC monographs. Lyon, France: International Agency for Research on Cancer. https://monographs.iarc.who.int/iarc-monographs-preamble-preamble-to-the-iarc-monographs/
Lawlor DA, Tilling K, Davey Smith G. 2016. Triangulation in aetiological epidemiology. Int J Epidemiol. 45(6):1866–1886. 28108528
Lunn RM, Mehta SS, Jahnke GD, Wang A, Wolfe MS, Berridge BR. 2022. Cancer hazard evaluations for contemporary needs: Highlights from new National Toxicology Program evaluations and methodological advancements. J Natl Cancer Inst. 114(11):1441–1448. 10.1093/jnci/djac164 36029241
National Academies of Sciences, Engineering, and Medicine (NASEM). 2022. Workshops to support EPA's development of human health assessments: Triangulation of evidence in environmental epidemiology, May 9–11, 2022. Washington, DC: National Academy of Sciences. https://www.nationalacademies.org/event/05-09-2022/workshops-to-support-epas-development-of-human-health-assessments-triangulation-of-evidence-in-environmental-epidemiology
National Toxicology Program (NTP). 2015. Handbook for preparing Report on Carcinogens monographs. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, Division of the National Toxicology Program, Office of the Report on Carcinogens. https://ntp.niehs.nih.gov/go/rochandbook
National Toxicology Program (NTP). 2021a. NTP cancer hazard assessment report on night shift work and light at night. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/NTP-CHR-NSWLAN
National Toxicology Program (NTP). 2021b. The Report on Carcinogens [fact sheet]. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. https://ntp.niehs.nih.gov/sites/default/files/ntp/pressctr/factsheet/15th_roc_508.pdf
National Toxicology Program (NTP). 2021c. Substance profile: Benzidine and dyes metabolized to benzidine. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2021d. Substance profile: Cobalt. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2021e. Substance profile: Cumene. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2021f. Substance profile: Diazoaminobenzene. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2021g. Substance profile: Ethylene oxide. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2021h. Substance profile: Trichloroethylene. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2021i. Substance profile: Viruses, eight listings. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2023. Report on Carcinogens process & listing criteria. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. [Last updated: March 7, 2023]. https://ntp.niehs.nih.gov/go/rocprocess
Rothman KJ, Greenland S. 2005. Causation and causal inference in epidemiology. Am J Public Health. 95 Suppl 1:S144–S150. 10.2105/AJPH.2004.059204 16030331