# 6 Evaluation of Mechanistic Information

## Summary

This section of the handbook provides a transparent framework using systematic review and integration methods and guidance, aligning with the Report on Carcinogens (RoC) listing criteria, for reaching a level-of-evidence (LoE) conclusion for carcinogenicity from mechanistic studies. Key elements are (1) using fit-for-purpose approaches, (2) providing a structural framework for evaluating study informativeness and reaching confidence judgments and LoE, (3) using strategies accepted by the scientific community (such as the key characteristics of carcinogens [KCC]), and (4) encompassing scientific advancements and New Approach Methodologies (NAMs) (e.g., read-across approaches).

The first component of the handbook describes steps for conducting broad scoping and evidence-mapping activities to develop a fit-for-purpose health hazard framework and study protocol for the specific substance. The framework identifies influential mechanistic questions and the literature (referred to as study sets) that will be used to answer the questions. These questions are scientific issues that (1) are critical for understanding cancer mechanisms and biological and human relevance, (2) will most likely impact the LoE conclusions (e.g., establishing or refuting biological plausibility), and (3) have an adequate database to assess; examples include the confidence for a biological effect(s) (such as a KCC), mechanism of action (MoA), or prediction of carcinogenicity based on read-across analysis. Each study set is defined by the type of evidence (e.g., exposed humans or animals), exposure, comparison, group, and endpoint (e.g., a specific biomarker or similar biomarkers).

The second component provides study informativeness questions for evaluating mechanistic studies in exposed humans, animals, and cells and has biomarker and assay information for the 10 KCCs to assess the informativeness of selected study sets for each question. The rigor (e.g., streamlined, moderate, in-depth) of the study informativeness and evidence assessment depends on how impactful a study set is to the overall evaluation. The last component of our handbook describes a three-step process for integrating the evidence across studies in each study set, across study sets to reach a confidence judgment for each influential question (e.g., confidence for a KCC, MoA, read-across prediction), and across questions for an LoE conclusion from mechanistic studies. Descriptors and guidance are provided for confidence levels (e.g., high, moderate, low) for each type of mechanistic evidence (including the “ideal” evidence for high confidence for specific KCCs) and LoE (convincing, supporting). “Convincing” (as defined by the RoC listing criteria) refers to LoE from mechanistic studies that allows a substance to be listed as a human carcinogen with insufficient or inadequate evidence from cancer studies in humans or animals, whereas “supporting” LoE refers to robust mechanistic data supporting the findings in human or animal cancer studies.

The LoE from mechanistic studies is integrated with LoE from human cancer epidemiological and animal cancer studies, considering all relevant data to reach a listing recommendation.

## Introduction

Mechanistic data—studies on how a substance causes cancer or other diseases—are often crucial for identifying cancer hazards. For the RoC evaluations, the evaluation team identifies and assesses the relevant mechanistic information to determine the strength of the evidence (i.e., conclusion) for the biological plausibility that a substance may cause cancer in humans, that the animal cancer data are relevant to humans, or both. Using the RoC listing criteria (https://ntp.niehs.nih.gov/go/rocprocess), this conclusion is integrated with the LoE conclusions from human and animal cancer studies to reach a preliminary listing recommendation for the substance. Cancer studies can also inform the evaluation of mechanisms by providing information on type of tumor and can be useful for identifying sensitive populations. When human or animal cancer evidence is limited or inadequate, convincing mechanistic information is needed to fulfill the RoC listing criteria. Mechanistic evidence is also evaluated when there are robust data from human and animal cancer studies. RoC evaluations use the term “supporting mechanism data” for evaluations mainly relying on human or animal evidence, with mechanistic data showing biological plausibility, but by itself may be less than convincing. RoC evaluations may lead to the discovery of new mechanisms for a substance (see Section 6.4.3). Guidance for reaching convincing or supporting LoE is provided in Section 6.4. Understanding cancer mechanisms may sometimes help inform the approach for assessing (e.g., most relevant exposure metrics, latency, and timing of exposure) and interpreting the evidence from human cancer studies (e.g., biological plausibility for specific cancers). Table 6-3 to Table 6-5 provide an example, trichloroethylene review, which assesses the evidence for a given hypothesis (or MoA), B-cell antigen stimulation, was evaluated as a potential mechanism for non-Hodgkin lymphoma, a cancer observed in human and animal studies.

### Cancer Mechanism Evaluation Process

The assessment of cancer mechanisms begins with scoping and problem formulation leading to the development of the framework (which is captured in the protocol) for a specific substance under review. Using the methods delineated in the protocol, a project team conducts the evaluation, which includes assessing informativeness and evaluating and integrating the evidence of the selected studies and data to reach the strength or LoE conclusions (see Figure 6-1).

Figure 6-1

Cancer Mechanism Evaluation Process

The schematic depicts the systematic review process, which begins with identifying the substances, searching and mapping the evidence (Step 1a, Section 6.2.1), and developing the protocol (Step 1b, Section 6.2.2). Iterative scoping questions can help inform the framework (e.g., identify the questions and literature [e.g., EECO] most influential to the evaluation) and approach for evaluating study informativeness for a specific substance under the review. The framework is captured in the substance protocol (Step 1c, Section 6.2.6). Using the protocol guidance, we evaluate the informativeness (focusing on the most predominant biases) of the relevant literature for each influential question (Step 2, Section 6.3) and evaluate and integrate the evidence by a multistep process to reach level-of-evidence (LoE) conclusions (Step 3, Section 6.4). EECO = evidence type (e.g., human, animal, in vitro, cell-free system, in silico), exposure, comparison group, and outcome; it is analogous to PECO, with “evidence type” replacing “population”).

### Cancer Hazard Assessment and Handbook Components

The handbook provides the methods to develop a substance-specific guidance framework (protocol) and guidance for evaluating study informativeness and integrating the evidence to reach an LoE of carcinogenicity from mechanistic studies. To facilitate understanding the methods for assessing mechanistic evidence, we first discuss considerations in method development (Section 6.1), followed by the methods for each step (as per Figure 6-1) in the cancer hazard evaluation process.

- Develop the cancer hazard framework for mechanistic data (Section 6.2).
  - Develop and execute a literature search strategy to search, identify, and map the literature.
  - Develop the framework or protocol.
- Evaluate the informativeness of individual—or groups of similar or influential—mechanistic studies or computational models (Section 6.3).
- Evaluate and integrate the evidence via a multistep process—and reach an LoE conclusion of carcinogenicity from mechanistic studies (Section 6.4).

Clustering and read-across approaches encompass developing and conducting analyses besides scoping and evaluating the evidence, and considerations in the process steps may overlap. Thus, Section 6.5 integrates and discusses the methods across the evaluation process.

## 6.1 Aims and Considerations for Developing the Methods

The handbook builds on and provides transparency to prior approaches used to evaluate mechanistic information for substances listed in the RoC. Recent advancements in identifying, organizing, and assessing mechanistic data related to cancer [notably as outlined in the 2019 International Agency for Research on Cancer preamble (IARC 2019; Samet et al. 2020)], scientific innovations for generating mechanistic data, and the growing reliance on using these data also informed these methods. In documenting our methods for assessing mechanistic data, we aim to:

- Use strategies for evaluating mechanistic data that are accepted by the scientific community (see Section 6.1.1).
  - Incorporate read-across approaches (see Sections 6.1.1 and 6.5) and scientific advancements (see Section 6.7).
- Provide transparency for a structured approach for methods used to reach conclusions based on the RoC listing criteria (see Section 6.1.2).
  - Develop new guidance for determining the informativeness of individual studies (Section 6.3) and collective evidence evaluation and integration (Section 6.4).
- Conduct fit-for-purpose evaluations focusing on the influential issues identified by broad, unbiased scoping activities (see Section 6.1.3 and Section 6.2).

### 6.1.1 Use Strategies for Evaluating Mechanistic Data

Mechanistic data are often derived from ex vivo, in vitro, in chemico, biochemical, or in silico studies, informed by chemical properties. They typically explore early molecular and cellular effects leading to tissue- or organ-level responses or changes in biological functions. Mechanistic information may also be derived from in vivo studies in animals and observational, randomized, or volunteer studies in humans. We define evidence type as testing system (i.e., in vivo, in vitro, in silico, and in exposed humans [including observational and interventional human studies with endpoints other than cancer incidence]). NAMs, such as advanced computational models and multiomics, are being developed and implemented to predict carcinogenicity without relying solely on animal models (see Section 6.7, New Directions). As the scientific consensus for using NAM and multiomics data in cancer hazard assessment advances, we will update the handbook to include methods to assess (e.g., study informativeness), evaluate, and integrate these types of data.

#### Biological Responses and Pathways

Carcinogenicity involves the acquisition of properties associated with the transition of normal cells to cancer cells. Hanahan and Weinberg describe these functional properties of cancer acquired by human cells as the hallmarks of cancer (2011). Since the 2011 publication, new and emerging hallmarks have been identified (Hanahan 2022) (see Box 6-1). Carcinogens can cause cancer through a multistep process. The acquisition of these functional capabilities might be mapped in some fashion to the distinguishable steps of tumor pathogenesis (Hanahan 2022). Sequential biochemical events and perturbations in the biological system resulting in the formation of cancer are described by two terms: mode(s) of action (MoA) and adverse outcome pathway(s) (AOP) (Rowan and Spielmann 2019). An MoA includes the sequence of obligatory (key) biological events from cellular interaction with the chemical to a functional or biological effect within a living system (Kienzler et al. 2017). An AOP is a conceptual model that includes the key cellular and molecular events, beginning with a Molecular Initiating Event (MIE), required to produce an adverse effect from exposure to a toxicant and is not chemical specific (NTP 2023). Mechanism(s) of action refers to a detailed understanding at a biochemical and molecular level of how a substance causes an adverse health effect (Jacobs et al. 2020). In this handbook, we use the term MoA to be either mechanisms or modes of action because a similar approach and guidance is used for both concepts. A MoA can also be thought of as a hypothesis.

Box 6-1 Hallmarks of Cancer

Hallmarks | Emerging Hallmarks
Sustaining proliferative signaling Evading growth suppressor Resisting cell death Enabling replicative immortality Inducing or accessing vasculature Activating invasion and metastasis Deregulating cellular metabolism Avoiding immune destruction Enabling: • Genome instability and mutation • Tumor-promoting inflammation | Unlocking phenotypic plasticity Senescent tumor cells Enabling •Nonmutational epigenetic reprogramming • Polymorphic microbiomes

Sources: Hanahan (2022).

^a^ Cancer stem cells and the tumor microenvironment are now widely appreciated to play an integral role in tumorigenesis and malignant progression and could be considered emerging hallmarks.

Carcinogens induce tumors through multiple mechanisms and biological pathways (Guyton et al. 2009; Smith et al. 2020), and a complete understanding of all cancer mechanisms for a given substance is rarely, if ever, known. Thus, assessments of mechanistic data focusing only on proposed MoA or AOP may miss additional mechanisms or reach erroneous conclusions. Informed by a review of over 100 known human carcinogens, an IARC working group identified shared initiating properties of human carcinogens (i.e., the key characteristics of carcinogens [KCCs]), which collectively encompass multiple cancer mechanisms (see Box 6-2). The KCCs provide an unbiased way to find, organize, and evaluate relevant mechanistic literature without reliance on a predetermined cancer formation pathway (Guyton et al. 2018; Smith et al. 2016; Smith et al. 2020). IARC developed a framework for using this approach (captured in the 2019 Preamble) and has applied it to over 50 cancer hazard evaluations (IARC 2019; Smith et al. 2020). With increasing knowledge of cancer mechanisms and testing technology innovations, the list of KCCs is expected to grow (Tice et al. 2021). In recent years, RoC monographs have also used the KCC approach in their cancer hazard evaluations (e.g., Night shift work, light at night), including those for the RoC (e.g., haloacteic acids found as water disinfection by-products, antimony trioxide) (NTP 2018a; 2018b; 2021a).

Box 6-2 Key Characteristics of Carcinogens

KCC 1. Is electrophilic or can be metabolically activated to an electrophile

KCC 2. Is genotoxic

KCC 3.Alters DNA repair or causes genomic instability

KCC 4. Induces epigenetic alterations

KCC 5. Induces oxidative stress

KCC 6. Induces chronic inflammation

KCC 7. Induces immunosuppression

KCC 8. Modulates receptor-mediated effects

KCC 9. Causes immortalization KCC 10. Alters cell proliferation, cell death, or nutrient supply

Source: Smith et al. (2016); Smith et al. (2020).

#### In Silico Clustering and Read-across Approaches

Read-across represents an important data-gap filling technique for chemical safety assessments. Interest in clustering and read-across approaches and other new classification methodologies, as part of NAMs, for identifying hazards has been increasing due to the large number (>350,000) of chemicals (globally) registered for production (Wang et al. 2020) and use with a paucity of human and animal cancer data. Grouping chemicals with similar properties circumvents the time needed, costs, and use of experimental animals. However, few reports of using these methods to predict cancer are available, perhaps due to the complexity of carcinogenesis.

Clustering approaches involve grouping similar compounds based on functional groups, chemical class, precursors, or physicochemical and biological properties. Unsupervised clustering approaches use input data (such as general structural characteristics not specific to an endpoint) without a corresponding predicted variable or endpoint of interest. General unsupervised clustering through structural similarity alone may not provide information on biological activity or function but can be used in scoping activities to inform a read-across plan (see Section 6.5). Typically, supervised classification approaches are used to predict an outcome and involve training a model using input variables (specific for the endpoint), the endpoint of interest or data-gap filling (e.g., outcome variable), and an algorithm to map the input to the output. Supervised learning can also use modern artificial intelligence (e.g., deep neural networks) based on specific biological endpoints.

Read-across based on grouping chemicals with structural and biological similarity and using source chemicals with known cancer hazards (with human or animal cancer data) is utilized to predict the cancer hazard of the target chemical. There are two main approaches to read-across: analogue and category. In the analogue approach, empirical data from one or a group of analogue source chemicals can be used to predict the same endpoint for the target chemical through endpoint specific supervised similarity. The category approach predicts targets starting from a group or a category of multiple sources whose physical-chemical, biological, or toxicological properties are likely to be similar or follow a regular pattern as a result of structural similarity (OECD 2014). For confidence in the read-across prediction, a robust assessment of uncertainty from multiple sources in the read-across process is undertaken (Schultz et al. 2015).

RoC listings include several chemical classes based on metabolism to a carcinogen (e.g., dyes metabolized to benzidine) (NTP 2021b) or a similar MoA (cobalt and cobalt compounds that release cobalt ions in vivo) (NTP 2021c). We aim to expand our assessment of chemicals by incorporating read-across approaches in our cancer hazard evaluations.

### 6.1.2 Structured Guidance for Reaching Conclusions

New to the updated handbook are guidance considerations and a structured framework for determining whether the mechanistic evidence is convincing. These new features include guidance for evaluating the quality of the mechanistic studies, confidence guidance for different types of information (e.g., read-across, biological effects or responses), and guiding principles for the overall body of evidence. Our approach also provides transparency for a stepwise approach to evidence integration that builds on methods used in previous evaluations. We aim to find a “sweet spot” between “adequate transparency and consistency across evaluations” and “flexibility for substance-specific issues and scientific judgment” (i.e., to avoid prescriptive algorithms).

The RoC listing criteria (https://ntp.niehs.nih.gov/go/rocprocess) provide several means (each of which can be viewed as a criterion) for listing in the RoC based on mechanistic data. To provide transparency and develop a structured framework for evaluating mechanistic evidence, we coined the term “Level of Evidence mechanistic question” and developed guidance for each element of the RoC criteria that is related to the evaluation of mechanistic (and related, such as class approaches) evidence.

The LoE of carcinogenicity from mechanistic data is reached by answering one or more of the LoE questions (see Table 6-1) and considering all relevant data. LoE question 1 (whether the agent acts through mechanisms indicating it would likely cause human cancer) encompasses the concepts of biological plausibility, answered by using mechanistic strategies evaluating (1) biological effects (e.g., KCCs) or MoA or (2) using read-across strategies to predict the carcinogenicity of nonlisted substances. Read-across approaches can also be used to evaluate whether the substances under review are members of similar classes as listed substances (LoE Question 2), and MoA approaches are also used to address whether there is compelling evidence that a substance acts via a mechanism that does not operate in humans (LoE Question 3) (see Table 6-1). In this handbook, we develop strategy-specific (e.g., biological effects, MoA, read-across) confidence judgments (e.g., high, moderate, and low) and guidance to reach “convincing” and “supporting” LoE conclusions (see Section 6.4 for biological effects and MoA and Section 6.5 for read-across).

Table 6-1 The Relationship between LoE Questions and Mechanistic Strategies

Criteria-related Questions | Mechanistic Strategies for Answering the Question
1. What is the level of evidence (LoE) (convincing, supporting) that the agent acts through mechanisms indicating it would likely cause cancer in humans?
Biological plausibility | Biological effects/KCC, including the relationship between two or more KCCs. One or more structured and reported MoA (e.g., cancer site specific or cancer pathway, such as endocrine disruption)
Predicted to cause cancer | Read-across methods incorporating mechanistic data
2. Does the agent, substance, or mixture belong to a well-defined, structurally related class of substances whose members are listed in a previous RoC (known to be a human carcinogen or reasonably anticipated to be a human carcinogen)? | Read-across methods incorporating mechanistic data
3. Are there compelling data indicating the agent acts through mechanisms that do not operate in humans and therefore are not “reasonably anticipated” to cause cancer in humans? | MoA for a specific cancer site

### 6.1.3 Fit-for-purpose Evaluations

One of the primary challenges of a mechanistic data review is the potentially large number of relevant references. An in-depth comprehensive review of all relevant studies is impractical and may not be necessary for hazard assessment. Instead, the goal is to rigorously assess and evaluate the confidence in the evidence for the most “influential mechanistic questions” for the substance under review. These questions are related to the LoE questions and strategies (see Table 6-1) but are substance specific, e.g., an influential question would focus on specific KCCs for which there is an adequate database to review and likely to impact (supporting or arguing against a listing) the overall assessment. A typical cancer hazard evaluation will have several influential mechanistic questions, which are identified through scoping activities—including broad-based comprehensive literature searches and evidence mapping, a series of iterative guiding questions, authoritative and other relevant reviews, and a preliminary review of the human and animal studies, e.g., cancer sites observed in human and animal studies or cancer sites that may not be relevant to humans. For each question, the rigor of the study informativeness assessment (bias evaluation and study sensitivity) depends on how impactful the different groups of studies are to the overall evaluation (see Section 6.2.2). The overall LoE is reached by integrating confidence in the evidence across the questions (see Section 6.3 and Figure 6-2). Although the cancer hazard evaluation (captured in the monograph) focuses on the influential questions, the monograph will briefly summarize all relevant mechanistic data in the evidence integration step. Identifying key questions has been successfully used since 2013 for RoC monographs (see Section 6.2.2, Protocol Development for examples). Although the fit-for-purpose approach provides for flexibility for the specific substance, the major steps (and guidance) in Figure 6-2 are common to all evaluations.

Figure 6-2

Fit-for-purpose Evaluations

Influential mechanistic questions are identified from broad, unbiased literature searches. For each question, the relevant literature (e.g., multiple study sets) is identified and evaluated; the rigor (streamlined to in-depth) of the study informativeness and evidence assessment depends on how impactful or influential (e.g., low to high) a study set is to the overall evaluation (see Sections 6.2 and 6.3, Box 6-3). Each study set is defined by the type of evidence (e.g., exposed humans or animals, in vitro), exposure, comparison, group, and endpoint (e.g., a specific biomarker or similar biomarkers) and are informed by evidence mapping and the influential questions. Lastly, we integrate the evidence across study sets to reach a confidence judgment for each question and across questions for an LoE conclusion.

## 6.2 Mechanistic Framework Development

To develop the framework, the project evaluation team performs scoping and problem formulation activities, which are used to create a protocol (e.g., methods) to conduct the evaluation. Whereas Section 1 discusses scoping and problem formulation activities for the overall cancer hazard evaluation, this section focuses on methods specific for the review of mechanistic studies. The process is necessarily iterative (i.e., there may be several cycles of literature searches and evidence mapping). The development of the mechanistic framework for read-across approaches is discussed in Section 6.5.

Figure 6-3 provides an overview of the framework development process. When a new substance is identified for potential review, scoping activities begin with a review of authoritative reviews and other scientific information sources, many of which are listed in the general sources found in Appendix B (e.g., EPA CompTox Chemicals Dashboard (https://comptox.epa.gov/dashboard/), NTP Integrated Chemical Environment (https://ice.ntp.niehs.nih.gov/), OECD eChemPortal (https://www.oecd.org/chemicalsafety/risk-assessment/echemportalglobalportaltoinformationonchemicalsubstances.htm), ECHA REACH (https://echa.europa.eu/regulations/reach/understanding-reach)) and initial literature searches to gather mechanistic information for the substance and develop the initial EECO statement (Evidence type, Exposure, Comparison group, and Outcome), which informs the literature searches and inclusion and exclusion criteria to select the literature. Next, broad-based systematic literature searches and searches for omic and screening biological effects data in recognized data depositories are conducted. Iterative scoping questions and mapping the evidence from literature searches (e.g., by KCC, evidence type, or MoA) and authoritative reports help to focus the evaluation, e.g., identify the influential questions, and literature (i.e., study sets) to answer those questions. Each study set is defined by the ECCO specific for the question. Finally, the framework is captured in the substance protocol.

Figure 6-3

Framework Development Schematic

Literature searches and inclusion and mapping of the relevant literature are conducted based on the initial EECO. These scoping activities help to identify the influential questions and the literature used to answer those questions (e.g., the influential question EECO), which are termed study sets.

### 6.2.1 Literature Search Strategy and Selection

The information specialist conducts a broad-based literature search in PubMed and at least one other citation database (e.g., Scopus or Web of Science) using substance-specific search strings (e.g., exposure) combined with KCC-specific terms (outcome or endpoint) or general mechanism terms (using the Boolean operator “AND”). General mechanism terms capture MoA or other mechanistic data that may be missed by restriction to KCC terms (see the search string document (https://ntp.niehs.nih.gov/whatwestudy/assessments/cancer/handbook/index.html) on the NTP website for the search strings for KCCs and general mechanisms). Table 6-2 provides examples of the terms and concepts (not an exhaustive list) covered in the searches. Substance-specific search strings are available in the substance protocol. Using KCCs to search for mechanistic data provides an unbiased literature search that is not targeted to any one mechanism. These searches may be supplemented with terms for substance-specific issues.

Table 6-2 Examples of Concepts Used for Mechanism Searches

Mechanism Searches | Example Concepts
Mechanism Searches | PubMed, Scopus, Web of Science | MeSH Terms
General Mechanism Search Terms | Biological markers Biomarkers Key events Mechanism/mode of action Molecular initiating event | Causality Tumor markers, biological Etiology [sh] Oncogene fusion Tumor necrosis factors
Characteristics of Carcinogens | See Box 6-2 above and the search string document
Metabolomics | Metabolome Global metabolism Systemic metabolism Epimetabolites Metabolic fingerprint Metabolomic-wide association study (MWAS) | Metabolomics

Citations are uploaded into a web-based program such as HAWC or SWIFT Active Screener, which has a machine-learning feature for screening and review. Inclusion and exclusion criteria are based on the initial mechanistic EECO (see Figure 6-3). The first round of screening is based on the title and abstract, whereas the second round is based on a full-text review. If needed, publications in other languages will be translated into English. Studies are typically organized and tagged by KCC, agent (if evaluating a class), and evidence type (e.g., exposed humans, exposed animals, in vitro). At times, the broad searches using KCC terms may yield a large database of available literature (e.g., 5,000+ articles). In these situations, a program such as SWIFT Review (a computer tool that assists with literature prioritization) (Howard et al. 2016) may be used to presort the literature by KCC, evidence type, or substance/agent based on key words in the title and abstract. As machine learning and artificial intelligence (AI) technologies improve, we may utilize these programs for evidence mapping and data extraction (Walker et al. 2022).

### 6.2.2 Evidence Mapping and Scoping Questions

Iterative scoping questions and evidence maps may help with problem formulation and identify the influential, agent-specific mechanistic questions and studies, prioritize publications for evaluations, and inform protocol development. A series of iterative scoping activities—e.g., literature searches and tagging, review of selected studies, streamlined data extraction, authoritative literature, and review of the human and cancer data—informs the development of these questions (see Figure 6-3). New or revised scoping questions are identified based on the answers to the initial questions. Computer tools (e.g., SWIFT Review, Dextr) can facilitate the reviewer-driven categorization of studies and data extraction. Examples of guiding questions from previous RoC reviews are found in Table 6-3. Evidence mapping using an interactive program such as Tableau can facilitate visualizing the literature, e.g., by agent, KCC, evidence stream, findings, or other relevant categories.

Table 6-3 Guiding Questions for Selected Example Evaluations

Substance | Example Scoping Questions^a^
Cumene (https://ntp.niehs.nih.gov/ntp/roc/thirteenth/monographs_final/cumene_508.pdf) (NTP 2013) | Are any tumors in experimental animals thought to be caused by species-specific mechanisms with an established MoA? • Is there an adequate database available to study the MoA and genotoxicity?
Trichlorethylene (TCE) (https://ntp.niehs.nih.gov/ntp/roc/monographs/finaltce_508.pdf) (NTP 2015) | What are the key events for the MoAs for the cancers observed in the human epidemiological studies—kidney cancer and non-Hodgkin Lymphoma (NHL)? • Does TCE cause immunotoxicity in experimental animals and autoimmune diseases in humans? • Are there data to evaluate the proposed mechanisms of immunomodulation and NHL?
Night Shift Work (https://www.ncbi.nlm.nih.gov/books/NBK571598/) Light at Night (NTP 2021a) | What is the relationship between circadian disruption and cancer? • What intermediate biomarkers of circadian disruption play a role in its pathogenesis? • What types of studies have evaluated circadian disruption and cancer? What circadian biomarkers and KCCs have been measured in night shift workers? Can mechanism information (e.g., biomarker studies on circadian disruption) help contextualize the potential cancer hazard from working night shifts? • What characteristics of night shift work are related to circadian disruption?
Antimony Trioxide (https://ntp.niehs.nih.gov/go/ROCMGRAPH13abs) (NTP 2018a) | What role do antimony chemical species play in antimony trioxide carcinogenic potential? • Is there a difference in toxicity or carcinogenic potential between the pentavalent and trivalent forms of antimony? • Should mechanistic studies of other trivalent antimony chemicals be included in the evaluation?
Haloacetic Acids (HAA) (https://doi.org/10.22427/ROC-MGRAPH-12) (NTP 2018b) | What are the major MoA(s) for the carcinogenicity of HAAs? • Do all or some HAAs share an MoA or cause similar key biological events? • How does a potential MoA relate to the bio-physical properties of HAA and the KCC? • How do the animal cancer outcomes relate to HAA mechanistic data or physicochemical properties? Do the mechanistic and other relevant data provide adequate support for considering some or all HAAs as a well-defined, structurally related class?

^a^ These questions have been modified from key questions in the protocols or workshop documents. (Note that cumene predates the development of a public protocol.)

### 6.2.3 Deposited Data Searches

On a case-by-case basis (to potentially supplement traditional mechanistic data based on a focus or specific need), we may search data repositories for omic and other high-throughput data (e.g., ToxCast/Tox 21) related to potential cancer mechanisms and related peer-reviewed publications (e.g., study design and methods). For example, the NTP cancer hazard evaluation of antimony trioxide included an analysis comparing bioactivity of different antimony compounds (NTP 2018a). In general, these types of data are used to support the evaluation but do not currently influence the evaluation. Examples of repositories and tools for analyzing the data include Gene Expression Omnibus (NCBI 2023) and SpiderSeqR (Sozanska et al. 2020), which searches high-throughput multiomic data repositories. The substance-specific protocol will provide the methods for data analyses.

### 6.2.4 Identifying Influential Mechanistic Questions and Study Sets

As mentioned in Section 6.1.3 (Fit-for-purpose Evaluations), we aim to focus our evaluations by identifying several “influential” mechanistic questions. These are scientific issues that (1) are critical for understanding cancer mechanisms and biological and human relevance, (2) will most likely impact the LoE conclusions (e.g., establishing or refuting biological plausibility) and (3) have an adequate database to assess. Focusing the literature on these questions does not bias the assessment because the questions are identified based on broad scoping activities (e.g., using KCC terms) and iterative guiding questions. An influential mechanistic question might be related to a single or group of related biological effects or responses (and the connections between these effects), biological pathways (or MoA) reported in the literature, or whether the substances (or subclass) belong to a carcinogen class. Currently, most biological effects of interest are captured by the 10 KCCs, but this may change with knowledge gained by scientific advancements. The set of questions for each evaluation may overlap and would most likely (if the database is adequate) represent several pathways for which a substance can cause cancer; for instance, an evaluation with a question for a specific MoA would also include questions that are pathway agnostic (e.g., based on a KCC). Table 6-4 provides examples of selected influential mechanistic questions from previous evaluations that were developed from the guiding questions in Table 6-3.

The evaluation of mechanistic data may help identify new pathways (e.g., assessment of KCCs and the relationship between KCCs or from integrating data from multiomic studies) or help inform the confidence for cancer sites observed in humans (e.g., cancers with limited evidence, such as the trichloroethylene [TCE] and non-Hodgkin lymphoma [NHL] example) or animal cancer (e.g., human relevance, such as the cumene male rat kidney tumor example).

The protocol will also identify the EECO for the literature (e.g., study sets) or data needed to address each influential mechanistic question (see Figure 6-3). For example, a question related to genotoxicity would include studies from different evidence types evaluating diverse biomarkers. For many evaluations, interactive evidence maps are created, allowing for real-time identification of the exact studies.

Table 6-4 Influential Mechanistic Questions for Example Evaluations

Substance | Example Influential Questions^a^ | Cancer Hazard Conclusions
Cumene (https://ntp.niehs.nih.gov/ntp/roc/thirteenth/monographs_final/cumene_508.pdf) Reasonably anticipated to be a human carcinogen (NTP 2013) | What is the confidence that cumene causes renal tumors in male rats by MoA that is considered not to be relevant to humans (i.e., alpha(2u)-globulin nephropathy)? What is the confidence for the relevance of mouse lung tumors to humans? What is the confidence that cumene causes genotoxicity, and at what tissue sites? | Sufficient evidence of carcinogenicity from experimental animals^b^ • Liver and lung tumors: considered human relevant • Kidney tumors supporting as relevance to humans is unclear Genotoxic in some tissues
Trichlorethylene (TCE) (https://ntp.niehs.nih.gov/ntp/roc/monographs/finaltce_508.pdf) Known to be a human carcinogen (NTP 2015) | What is the confidence level that TCE can cause kidney cancer via a glutathione conjugation (GSH) pathway (e.g., bioactivation of TCE to nephrotoxic and mutagenic (in the kidney) metabolites)? What is the confidence level that TCE can cause lymphoma via an immunomodulation mechanism involving B-cell activation via chronic antigen stimulation (leading to B-cell oncogenic transformation via mutations/genomic recombination during class switching and somatic hypermutation)? • This question differs from a general KCC question regarding whether TCE causes chronic inflammation or immunomodulation as it focuses on a specific type of immunomodulation that is proposed to be linked to non-Hodgkin lymphoma (NHL). • The confidence for this MoA can be combined with limited evidence from cancer epidemiology studies to reach a conclusion related to the level of evidence in humans (e.g., cancer epidemiological studies and mechanistic studies). | Sufficient evidence from studies in humans: kidney cancer • Supporting evidence from toxicological, toxicokinetic (e.g., GSH metabolism), and mechanistic studies (e.g., genotoxic and nephrogenic metabolites in the kidney)^c^. • Limited evidence from studies in humans: Supporting evidence for autoimmunity and immunosuppression, but B-cell activation hypothesis was not adequately tested
Night Shift Work (https://www.ncbi.nlm.nih.gov/books/NBK571598/) Persistent night shift that causes circadian disruption High confidence for a causal relationship with human cancer (NTP 2021a) | What is the confidence that circadian disruption plays a role in nightshift work carcinogenicity? • What is the confidence that circadian disruption causes cancer? • What is the confidence that night shift work is associated with circadian disruption? What is the confidence that night shift work causes KCCs (specifically, genotoxicity, oxidative stress, immune effect, increased hormones, and epigenetic effects)? • Are KCCs observed in humans the same as the KCCs detected in animal cancer studies? | Sufficient evidence from the collective body of evidence of cancer epidemiological studies (limited by itself) and mechanistic studies in humans and experimental animals^d^ • Circadian disruption plays a role in shift-work-mediated carcinogenicity • Night shift work is associated with KCC that were observed in animal cancer studies and with circadian disruption
Antimony Trioxide (https://ntp.niehs.nih.gov/go/ROCMGRAPH13abs) Reasonably anticipated to be a human carcinogen (NTP 2018a) | What is the confidence that antimony trioxide causes genotoxicity and KCCs (especially oxidative stress and receptor-mediated effects)? What is the confidence that other trivalent compounds cause KCCs (e.g., for which there are no data for antimony trioxide)? • What is the confidence that these can be attributed to antimony trioxide? | Sufficient evidence of carcinogenicity from studies in experimental animals and supporting mechanistic data • Antimony trioxide: Genotoxicity, oxidative stress • Other trivalent compounds: Inhibition of DNA repair, inhibition of cell differentiation • Antimony trioxide may exert its effects through released trivalent antimony ions
Haloacetic Acids (HAA) (https://doi.org/10.22427/ROC-MGRAPH-12) found as water disinfection contaminants (six) Reasonably anticipated to be a human carcinogen (NTP 2018b) | What is the confidence that HAAs cause genotoxicity and other biological effects (KCCs) (especially oxidative stress and electrophilicity)? • What are the molecular initiating events (MIE) and key steps, and how do they differ across HAAs? • Do the biological effects vary by the number and types of halogens? What is the confidence that HAAs without animal cancer data will likely cause cancer in experimental animals? • Can HAAs be grouped into subclasses based on animal cancer data? • Do individual HAAs (without cancer data) share key biological effects (or are metabolites) as carcinogenic HAAs? | Four HAAs sufficient evidence of carcinogenicity from studies in experimental animals and supporting from mechanistic data • Electrophilic, genotoxic, cause oxidative stress Two HAAs without animal data are listed in the RoC based on metabolism to a carcinogenic HAA and supporting mechanistic data. • Data insufficient to evaluate HAA as a class or subclasses^e^

^a^ Questions have been adapted (e.g., made more specific for illustrative purposes) from selected key questions in the monographs for these substances.

^b^ See Section 7.2.1, Box 7-1

^c^ See Section 7.1.3, Table 7-1

^d^ See other supporting information in Section 7.1.3, Table 7-1

^e^ See Section 6.5.3, Step 1, Exemplar

### 6.2.5 Technical Input and New Research

Experts with substance-specific expertise typically provide advice on the framework development or may peer review the evaluation protocol. The type of input—which is related to an influential mechanistic question—varies with the complexity of the evaluation and may range from consultation with individual technical advisors to information groups—experts who meet as a group and provide input on specific guiding questions or issues—to public workshops or webinars with experts giving presentations and focused panel discussions on multiple substance-specific scientific issues. NTP has also conducted additional studies to address research gaps related to influential mechanism questions. Table 6-5 provides examples of technical input and new research in past evaluations.

Table 6-5 Technical Input Strategies and New Research for Some Example Evaluations

Substance | Mechanistic Technical Input or Research
Cumene (https://ntp.niehs.nih.gov/ntp/roc/thirteenth/monographs_final/cumene_508.pdf) (NTP 2013) | Information group: Evaluation of the alpha(2u)-globulin nephropathy as the sole MoA for male rat kidney tumors Research: Genotoxicity studies were conducted because of conflicting findings and importance to potential species-specific mechanisms for mouse lung and rat kidney tumors. These studies showed that cumene cause DNA damage in the liver and lung in rodents.
Trichlorethylene (https://ntp.niehs.nih.gov/ntp/roc/monographs/finaltce_508.pdf) (NTP 2015) | Information group: TCE and immune effect studies for evaluating potential cancer mechanisms Rationale: Expert input is needed to evaluate a proposed mechanism (related to B-cell activation, see Table 6-4) for NHL, which is a cancer site of interest from human epidemiology studies.
Night Shift Work (https://www.ncbi.nlm.nih.gov/books/NBK571598/) (NTP 2021a) | Public workshop (https://ntp.niehs.nih.gov/events/webinars-workshops/2016/alan/index.html): 12-panel workshop addresses several scientific issues including (but not limited to) circadian disruption, how to define night shift work, and measures of circadian-effective light (Lunn et al. 2017).
HAAs (https://doi.org/10.22427/ROC-MGRAPH-12) (NTP 2018b) | Information group: Read-across strategies Rationale: Cancer bioassay data were only available for a subset of 13 HAAs considered for the evaluation. Expert input was needed to discuss whether read-across-like-approaches could be used to evaluate the potential carcinogenicity of subclasses of HAAs (e.g., based on the type or number of halogens) or individual HAAs without cancer data).

### 6.2.6 Protocol Development

The protocol for each assessment includes specific and detailed instructions and considerations for evaluating mechanistic information adapted from the general strategy presented in the RoC handbook. It summarizes the scoping activities (see Section 6.2.1), the evaluation framework (e.g., “influential mechanistic questions” and literature [study sets]), including the impactful literature (see Section 6.3), and the methods for assessing study informativeness and evaluating the evidence, including evidence integration (see Sections 6.3 and 6.4). When relevant, it includes clustering and read-across methods and a summary of technical input (such as an informational group or workshop). The protocol is informed by consultation with substance-specific experts.

## 6.3 Study Informativeness Assessment

As mentioned in Section 6.1, because there is an abundance of mechanistic studies, a fit-for-purpose approach is used that identifies the issues (e.g., influential questions) and the literature base to answers those questions (as discussed in Section 6.2). The focused approach also applies to the strategy for evaluating study informativeness, which is discussed in Section 6.3.1. Questions and guidance, organized by domains, are provided in Sections 6.3.2 for experimental in vitro and animal in vivo studies and 6.3.3 for exposed human studies. For the endpoint and analysis domains (Table 6-9 and Table 6-11), the questions and guidance are the same across all evidence types.

### 6.3.1 Strategy

The approach for assessing study informativeness consists of (1) identifying the influential literature and rigor of the evaluation (e.g., gradient ranging from streamlined to in-depth), (2) identifying biases and sensitivity concerns that have the maximum impact on the substance and evidence type under consideration (e.g., influential biases) (Savitz et al. 2019), and (3) assessing those issues across the influential literature and questions identified in the protocol (see Figure 6-4; details are discussed below). The steps in the process are similar across all evaluations, and the rigor and extent of the study evaluation are expected to vary depending on the complexity of the database.

Figure 6-4

Study Informativeness Approach

The fit-for-purpose study informativeness approach includes identifying the most impactful literature (1) and the level of rigor of the assessment and development of study-specific guidance that focuses on the most impactful issues (2). Questions and guidance to conduct the assessment (3) are modified from the general (domain-based) guidance for each evidence type provided in the handbook.

#### Identifying the Influential Literature and the Rigor of the Evaluation

The fit-for-purpose study informativeness approach includes identifying the most impactful literature. Mechanistic information frequently is found in a large set of studies. The rigor or depth of the evaluation (e.g., data extraction approach and study informativeness assessment) for each influential question can vary along a gradient (ranging from streamlined to in-depth), depending on the literature’s impact (or influence) on the overall evaluation (see Box 6-3 for guidance). For less impactful literature, a streamlined review may rely on reporting conclusions from credible or authoritative reviews without a formal study informativeness evaluation, while a moderate review may extract findings from primary studies and assess potential bias, and an in-depth evaluation of influential literature consists of detailed data extraction and formal study informativeness assessment as depicted in Figure 6-4 and discussed below). The protocol will outline the evaluation approach, including the influential literature and for reporting the findings and conducting the study informativeness assessment.

The light-at-night and night shift evaluations (NTP 2021a) provide an example of using this approach. Because the oncogenic effects of melatonin and clock genes have been well established, the evaluation relied on review articles for this information and conducted a deeper dive into the primary studies of KCCs and biomarkers of night shift work and light at night. (Note: The assessment considered general elements of study quality but did not conduct a structured study informativeness evaluation.) For TCE, immune studies required a more in-depth assessment to determine whether the measured biomarkers were consistent with the proposed MoA of B-cell antigen stimulation leading to lymphoma. Studies using similar methods to evaluate genotoxicity and oxidative stress of multiple HAAs and reporting trend and potency analyses were impactful in the evaluation of HAA subclasses for potential listing in the RoC.

Guidelines for identifying influential literature are provided in Box 6-3 and consider both the influential question and the adequacy of the database to answer the question. Deposited primary data (with published peer-reviewed methods or analysis guidelines) will be analyzed if the data are more informative (e.g., human relevant) than the published studies, answer a question for which there are no published studies, or inform biological networks or pathways.

Box 6-3 Guidelines for Identifying Influential Literature for Each Question^a^

How critical is the data to the overall cancer hazard listing recommendation?

- Are there adequate cancer studies in humans or experimental animals, or will the evaluation be primarily based on mechanistic studies?
- How will the mechanistic studies in exposed humans contribute to the overall conclusions regarding whether there is sufficient evidence from studies in humans?
- Is the literature and question associated with the cancer sites of interest?

What is the scientific consensus for the question (considering the evidence type)?

What is the adequacy (e.g., number of studies, human and biological relevance) of the database for each question? Is there an adequate database of biologically- and human-relevant studies?

How consistent is the evidence across a study set?

^a^Influential literature determines the degree of rigor of the review, e.g., study informativeness, reporting, and evaluation ranging from streamline to in-depth.

#### Develop Substance-specific Informativeness Guidance

During the scoping process, the study evaluation team identifies several impactful study informativeness issues specific to the exposure under evaluation; the evaluation protocol delineates these questions and guidance for evaluating the questions. The evaluation team adapts these substance-specific questions from the mechanistic-informativeness questions (e.g., exposure conditions or misclassification, endpoint assessment, confounding) for each evidence type (e.g., in vivo animal, in vitro, and exposed humans; see Sections 6.3.2 and 6.3.3). The study informativeness assessment concentrates on the impactful bias questions and does not necessarily provide responses for all the signaling questions in all the domains. Table 6-6 provides examples of impactful bias questions from evaluations of RoC-listed substances.

Table 6-6 Examples of Impactful Bias Questions

Substance | Domain | Evidence Type | Question/Comment
Cumene (https://ntp.niehs.nih.gov/ntp/roc/thirteenth/monographs_final/cumene_508.pdf) (NTP 2013) | Exposure/sensitivity | In vitro | Were the assays conducted using closed systems? Cumene is a volatile chemical, and this is a concern for false negatives.
Trichlorethylene (TCE) (https://ntp.niehs.nih.gov/ntp/roc/monographs/finaltce_508.pdf) (NTP 2015) | Confounding | In vitro | Is there potential confounding (most likely causing a false positive) from the presence of stabilizers or using DMSO as a solvent? DMSO can react with some TCE metabolites, raising the pH and distorting the findings.
Styrene (https://ntp.niehs.nih.gov/ntp/roc/twelfth/2010/finalbds/styrene_final_508.pdf) (NTP 2008) | Endpoint assessment | Exposed humans | A series of questions regarding the measurement of chromosomal aberrations and micronuclei was systematically assessed across studies.

#### Evaluation of Bias across Studies

For some evaluations, studies having similar designs, populations, exposures, or endpoint assessments may share similar concerns for potential bias and sensitivity. For example, randomized cross-over studies may be less susceptible to confounding than observational studies but only measure effects from acute exposure to the substance. In these cases, the evaluation may discuss study informativeness and evaluate the evidence for the group of studies (e.g., explore heterogeneity by experimental human studies vs. observational studies). The individual studies in the group are still reviewed, focusing on the shared influential biases and whether they can be binned together for bias assessment and evidence evaluation.

#### Bias Questions and Guidance

The evaluation team assesses the informativeness of mechanistic studies using a domain-based approach consisting of questions and guidance appropriate for the evidence type. As mentioned in the protocol section, bias assessment is fit for purpose, and the number of “impactful” biases may vary for different bodies of literature. For each question, we evaluate the potential, direction, and magnitude of the bias by comparing the study to an “ideal” study element specific to that bias (e.g., selection of participants). “Ideal” is defined as a study design condition resulting in low concern for bias or sufficient sensitivity to detect an effect if present (see Table 6-7 to Table 6-13 for guidance for each question). The bias assessment may identify a common issue (e.g., DMSO used as a solvent in the TCE studies), the degree of concern (e.g., minimal, some, major), for the bias, or overall informativeness for the issue (e.g., good, adequate, deficient). Because of the heterogeneity of mechanistic studies, guidance for these terms is provided in the substance protocol and not in the handbook. We use triangulation methods (e.g., integrating evidence with different approaches and different types of biases and to exploit these differences to draw qualitative conclusions; see Section 6.4) to explore bias impact across studies.

Two reviewers assess the studies and resolve differences through mutual discussion and reference to the original data source. To facilitate the review process and reduce ambiguity, we conduct a pilot phase using a small set of studies before proceeding with the complete evaluation. If reporting of the studies is too incomplete to evaluate bias, we will contact the study authors for additional details. See Section 6.6 for information on reporting.

### 6.3.2 In Vitro and In Vivo Animal Studies

The study informativeness assessment (guidance and questions) was informed by the animal cancer informativeness questions and the SciRAP Tool (http://www.scirap.org/Page/Index/ee9102de-4b17-4c3a-86b6-e3e70d6ca3d1/evaluate-reliability-and-relevance) for evaluating in vitro toxicology studies and other authoritative sources (USEPA 2018). As new tools are being developed to evaluate in vitro studies, we will reassess, and update guidance as needed. The in vitro and in vivo domains (study design, exposure conditions, outcome, confounding, and analysis) are similar; however, the guidance may vary by evidence type. Some study elements may overlap between different domains and will be addressed by one substance-specific influential bias question.

#### Study Design

Mechanistic studies may pose unique challenges because they often include multiple endpoints and assays with varying exposure conditions; assessment of the study design depends, in part, on the specific exposure and endpoint(s) under investigation.

The study design domain includes signaling questions that address bias and overall study sensitivity (Table 6-7). The in vivo studies have an additional bias question for randomization that is not relevant for in vitro studies. In vitro (and sometimes in vivo) studies generally also include positive (and, to a lesser extent, negative) control groups to verify the assay was conducted properly and was sensitive (or specific) enough to detect an effect and the results are treatment related.

In addition to evaluating bias and study sensitivity, experimental studies should consider reporting and other study quality factors, such as conditions that incorporate considerations of the model (pre-exposure), exposure, and endpoint domains. Ideally, assay conditions and procedures should be described in detail for cell or tissue/organ culture in vitro or ex vivo (before exposure, during exposure, and after exposure) and should follow best practices that approximate those described by Guidance for Good Cell Culture Practice (GCCP) (Pamies et al. 2022) and Good In Vitro Method Practices (GIVIMP) (OECD 2018a; 2018b; Pamies et al. 2022). This may include, but is not limited to, cell density, culture media, and culture conditions. Some of these issues may be confounding factors. However, it is recognized that not all these conditions are reported in the publications.

Core bias question: Is there concern that flaws in study design biased the interpretation of the findings?

Table 6-7 Study Design: Questions and Guidance

Study Design Signaling Question | Guidance: In Vitro | Guidance: In Vivo
Randomization
Is there concern that the methods by which animals were randomized to groups were inadequate or that animals were not randomized? | Not usually relevant. Note that randomization of replicates is addressed under endpoint assessment. | Ideally, the randomization method should be reported and based on ensuring all animals have an equal probability of being assigned to any given control or experimental group.
Controls
Is there concern that the concurrent control group/sample is not adequate for evaluating effects across treatment groups? | Control samples should be derived from the same cell line and handled in the same way as treated samples. An untreated or vehicle control should always be included as it is critical for determining treatment-related effects. In most cases, positive controls are important for in vitro studies to ensure the test system is functioning properly. | Concurrent controls are the most relevant comparison group for evaluating potential exposure-related biological effects. Both vehicle-treated and untreated controls should be used, with vehicle-treated being more relevant than untreated if only one type of control group was used. Ideally, the concurrent control group included at least as many animals as did each treatment group. In the absence of controls or the presence of only a few concurrent controls, historical controls from the same testing laboratory can be used. In some cases, positive or negative controls may be used to ensure sensitivity/specificity and detect bias.
Sensitivity Question
Is there concern that the study design was not sensitive enough to detect a mechanistic event or effect if present? | The overall sensitivity of the study design integrates the combined effects of several sensitivity factors—e.g., sensitive test system used, study duration, adequate replicates, and statistical power. One factor may compensate for limitations in another (e.g., a sensitive test system or positive control endpoint may compensate for low statistical power). Ideally, the in vitro models are biologically (e.g., metabolic capability, primary vs. cell line, proposed mode of action) and human relevant (e.g., human vs. mammalian cells, relevance to the cancer sites of interest). | The sensitivity rating integrates the animal model, statistical power, and study design. In some cases, one factor may compensate for limitations in another factor (e.g., a sensitive animal model may compensate for a low number of animals or short study duration).

#### Exposure Conditions

The study’s informative questions include a bias question related to dose selection and a sensitivity question related to dose levels, exposure duration, and frequency of exposure. Dose (or concentration) selection may affect both bias and study sensitivity. Sensitivity is decreased when doses are too low to induce an effect or too high and are cytotoxic. Bias (potentially resulting in a false positive) could occur if doses are high enough to nonspecifically induce the KCC via toxicity rather than direct (specific) effects on the KCC.

Core bias question: Is there concern that the exposure conditions biased the interpretation of the findings?

Table 6-8 Exposure Conditions: Questions and Guidance

Signaling Question | Guidance: In Vitro | Guidance: In Vivo
Dose Selection
Is there concern that the dose (concentration) levels were too high to attribute effects to the substance? | Ideally, the concentrations tested should not cause significant cytotoxicity that could affect study results. OECD may provide assay-specific guidance (GIVIMP) on dosing conditions, e.g., on the number and spacing of doses and dose levels (OECD 2018a; 2018b; Pamies et al. 2022). | Exposure should result in tolerable toxicity (e.g., slightly decreased survival and/or body weight gains) at the high dose, but not excess toxicity, for the duration of the study.
Overall Exposure Conditions Sensitivity
Is there concern that dose/exposure regimen was not sensitive enough to detect a relevant effect? | Exposure conditions sensitivity integrates several factors that may affect the ability of the study to detect an effect (e.g., dose levels that are too low and/or exposure durations that are too short). Ideally, the rationale for dose selection and number of doses should be reported and justified and follow guidelines for the assay. Ideally, exposure to the cells/tissues (e.g., uptake by cells) should be measured. The stability, solubility, and volatility of the test agent may affect exposure (e.g., lower the delivered dose); adjustments should be made as needed. Evaluation of dose response results can contribute to confidence in the study findings and allow for evaluation of potential effects at lower doses. | The sensitivity rating integrates considerations of dose level, route, exposure, and study duration (e.g., when the samples were collected). The selection of the dose may depend on the exposure duration. Ideally the delivered dose was close to the planned target dose (e.g., stability, solubility, volatility of the chemical; changes in eating and drinking patterns of the exposed group that may change the oral dose). The exposure route should consider metabolism of the chemical (e.g., a route that bypasses metabolic activation may not be informative). For many KCCs, long-term or repeated exposure studies are more informative for detecting persistent/chronic effects, which are more relevant for carcinogenicity. Many biomarkers are nonpersistent. Evaluation of dose response can contribute to confidence in the study findings and allow for evaluation of potential effects at lower doses.

#### Endpoint: All Evidence Types

Endpoint assessment includes considerations of how closely the measurement represents the endpoint of interest (e.g., KCC biomarker), how well the endpoint or biomarker is measured, and whether there is potential for observer bias (e.g., in the absence of blinding). Appendix D provides information for evaluating specific KCCs.

Core bias question: Is there concern that the endpoint assessment biased the interpretation of the findings?

Table 6-9 Endpoint Measurement: Questions and Guidance

Signaling Question | Guidance: All Evidence Types
Endpoint Proxy
Is there concern that the endpoint proxy (e.g., biomarker) did not represent the effect of interest? Is there concern that the biomarker was not measured in relevant tissue or cells? | Ideally, studies should measure the most relevant biomarkers related to the KCC biological effect (e.g., direct vs. indirect measures).^a^ In general, local biomarkers measured in local target tissues are more informative than those in circulation (systemic) or in other (nontarget) tissues.
Measurement Methods
Is there concern that measurement methods (e.g., timepoints, accuracy, precision) are not adequate to generate valid and reliable data? The measurement methods consider consistency, replication, randomization, and sampling (collection methods and timing). | Ideally, each study should use accurate and reliable methods for measuring each endpoint at the appropriate timepoint and should follow applicable protocols and guidelines. For some biological effects, there are OECD guidelines. The timing of sample collection is important to determine whether an observed effect is transient or persistent. The study should include enough replicates or repetitions to generate reliable results for the endpoint of interest and without any serious uncertainties or limitations in the sampling process. Replicate placement used in automated plate systems should be random.
Differential Measurement Error
Is there concern for differential measurement error (e.g., the treated and control groups were assessed differently)? | All treatment and control groups should follow the same protocols for endpoint assessment and should be clearly reported to properly interpret results. Blinding and randomization should be used during endpoint assessment.
Sensitivity Questions
Is there concern that the assay or methods were not sensitive enough to detect an effect? | Ideally, appropriate and sensitive assays (e.g., current state-of-the-science assays with sufficient counts, such as the number of cells) should be used to measure direct biological effects (e.g., KCC) in the target tissue or tissue of interest. However, multiple indirect measures may also be informative.

^a^ Informativeness for the KCC or biological effect; informativeness with respect to carcinogenicity is considered during evidence integration.

#### Confounding

Sources of potential confounding in both in vitro and in vivo studies include the chemical and its administration (e.g., vehicle, stabilizer, and conduct of the studies [e.g., cell culture maintenance, animal husbandry]). Chemical contaminants or other conditions that are associated with the endpoint may be potential confounders.

Core question: Is there concern about potential confounding?

Table 6-10 Confounding: Questions and Guidance

Signaling Question | Guidance: In Vitro | Guidance: In Vivo
Chemical Characterization
Is there concern that the chemical characterization and dose formulations (e.g., source, homogeneity, purity, solubility, volatility, and stability) are not adequate to support attribution of any effects to the substance? | Ideally, the source of the test agent should be identified, the purity and stability documented, and the solubility reported at the concentration used. A nontoxic vehicle should be used, and the test agent should be soluble in the vehicle. Contaminants or vehicles associated with the endpoint (e.g., genotoxic, immunotoxic) are potential confounders.
Substance Administration
Is there concern that the vehicle or stabilizers may have confounded the findings? | Vehicles and stabilizers, if used, should be verified not to interfere with exposure or endpoints of interest, even if a vehicle control group is used as the baseline.
Conduct Issues
Is there concern about confounding from the conduct of the study or maintenance of the animals or cells? | Examples of conduct that may lead to confounding if associated with the endpoint, in in vitro studies include cell culture maintenance, such as contamination of cell lines with bacteria or other cells, | Examples of sources of potential confounding (if associated with the endpoint) in animal in vivo studies include infection by pathogens, poor animal husbandry (e.g., impurities in the bedding), and decreased consumption of feed and water, leading to less healthy animals (e.g., in feed and water studies that alter smell and taste)

#### Analysis

Although not necessarily a bias, analyses are considered in the study informativeness evaluation. The study should identify and report the rationale for the statistical/analytical methods. Best practices (e.g., Organisation for Economic Co-operation and Development [OECD] test guidelines and corresponding guidance documents) provide some recommendations for statistical tests and general considerations for statistical analyses of different types of data. If necessary, the evaluation team will consult with statisticians and experts in data analysis. Biostatisticians will be consulted to evaluate omic data.

Core question: Is there concern that the data assumptions and analyses were not adequate?

Table 6-11 Analysis: Questions and Guidance

Signaling Question | Guidance: All Evidence Types
Data Assumptions
Is there a concern that the data assumptions used in the statistical analysis were inadequate? Is there concern that statistical methods used to investigate the endpoints were inappropriate, were not properly conducted, or were incomplete? | The study should clearly report all statistical methods and conclusions, any other methods, or information that is relevant for determining whether any observed effects are exposure related. For example, are data transformation methods (e.g., log transformation) appropriate? Were outliers removed? (Ideally, outliers should not be removed without statistical justification, as that may be where the effect is strongest.)
Statistical Model and Methods
Is there concern that statistical methods used to investigate the endpoints were inappropriate or not reliable? | The choice of statistical analyses will depend on the type of study and the nature of the endpoints measured.

### 6.3.3 Studies in Exposed Humans

Table 6-12 provides a summary of the approach for the study informativeness assessment and additional guidance in exposed humans. Assessment of observational studies in exposed humans follows the domain-based directions found in Section 3.2 (selection bias, exposure assessment, endpoint assessment, analysis, and sensitivity for human cancer studies). Other mechanistic studies in humans are controlled-exposure studies, e.g., randomized controlled trials or experimental studies of volunteers using themselves as the control (before or after exposure). For ethical reasons, experimental studies and interventions in humans are often for real-world exposures (albeit often for shorter times or lower frequencies) that individuals may have in their daily lives. Randomized controlled studies and other experimental studies may suffer from external validity and may not include relevant sensitive populations. For these controlled-exposure studies, bias from exposure conditions rather than exposure assessment is assessed. We have developed additional questions and guidance for the selection bias for these study types. Note that endpoint and analysis guidance are the same for all evidence types and are found above in Table 6-9 and Table 6-11.

Table 6-12 Study Informativeness Strategy for Mechanistic Studies in Exposed Humans

Domain | Strategy | Comment/Additional Guidance
Selection Bias | Observational studies: Human Cancer Studies (see Section 3.2) Experimental studies: Human cancer studies and additional questions/guidance on randomization and blinding | Same selection (including attrition) principles as case-control and cohort studies. Randomization Participants should be randomized appropriately for the study design (cross-over or other designs); the effectiveness of the randomization should be evaluated (i.e., are the distributions of important known confounders similar across treatment/exposure groups?) and reported. For cross-over trials, participants should be randomized with respect to the order of exposure and nonexposure periods, and there should also be an adequate wash-out period between exposure/treatment and subsequent nonexposed periods. Blinding: Ideally, participants and researchers should be blinded but this may not always be possible depending on the exposure type.
Exposure Assessment | Observational studies: Human Cancer Studies (see Section 3.2) | Exposure biomarkers and personal monitoring are more commonly used in mechanistic studies than cancer studies. Populations with prior, possibly chronic, exposure to the exposure of interest may lead to exposure misclassification and bias the findings toward the null (even if they were controlled-exposure studies). For example, some studies use self as controls.
Exposure Conditions | Experimental studies: New questions and guidance Sensitivity, bias, ethical considerations | Exposure levels should be high enough to detect the relevant effects. Similarly, duration and timing of dose(s) should be appropriate for manifesting the specific endpoint of interest. Ideally, they would be close to real-world exposure levels as practical. For many exposures, long-term or repeated exposure studies are often more informative for detecting certain biological effects (such as chronic inflammation), which are more relevant for carcinogenicity. The exposure conditions should be matched to the endpoint of interest.
Endpoint Assessment | All evidence streams (Section 6.2.2): Bias and sensitivity | Most studies measure circulating biomarkers rather than tissue-specific markers.
Confounding | Human Cancer Studies (see Section 3.2) | Information on potential confounders may be less common in mechanistic studies, and the association of a confounder may be less established. The nature of the exposure (e.g., exposure chambers) may cause stress, which can be an effect modifier.
Analysis | All evidence streams (see Section 6.2.2) | Biological effect biomarkers are often continuous data; thus, different statistical tests are used than those for cancer (ordinal outcome).
Study Sensitivity | Statistical power and exposure contrast: Human Cancer Studies (see Section 3.2) Endpoint: All evidence streams (Section 6.2.2) | Timing of endpoint measurement replaces latency. Long-term or repeated exposure studies are more informative for detecting persistent/chronic effects, which are more relevant for carcinogenicity.

## 6.4 Evidence Evaluation and Integration

### 6.4.1 Overview Strategy

The RoC listing criteria permit (1) listing a substance based on convincing relevant information that the agent acts through mechanisms indicating it would likely cause cancer in humans (e.g., in-depth analysis of mechanistic data related to biological plausibility) or is a member of a well-defined structurally related class of listed substances or (2) not listing a substance with sufficient evidence of carcinogenicity from laboratory animals but with compelling data indicating the agent acts through mechanisms that do not operate in humans (e.g., it is not biologically plausible). However, the listing criteria do not specify the bar for convincing, compelling, or determining whether a substance belongs to a listed class. Historically, we have used the terminology “supporting mechanisms” as part of the rationale for listing a substance in the RoC based on the evidence from human or animal cancer studies. Informed by lessons learned from previous evaluations and input from authoritative sources (e.g., IARC), we define guidelines for LoE conclusions (convincing or supporting) of mechanistic data. Our handbook also describes confidence descriptors and judgments for evaluating evidence for different mechanistic strategies (e.g., KCC, MoA, read-across analyses), which can be applied to the influential questions.

Box 6-4 Evidence Integration Steps

Evidence is integrated using a three-step process (see Box 6-4). After integrating the evidence across studies for each study set (see Section 6.4.2), the evidence is integrated across all study sets to reach a confidence judgment (high, moderate/limited, inadequate) for the influential question; confidence guidance is specific for different types of questions (e.g., KCCs, MoA, and read-across) (see Section 6.4.3). The third step (see Section 6.4.5) is to integrate the evidence across all the influential questions and other relevant data (e.g., absorption, distribution, metabolism, and excretion [ADME] and toxicokinetics) for a level of carcinogenicity (convincing, supporting) from mechanistic studies.

A series of evidence-based tables captures the assessment for each step, with conclusions for each step brought forth to the next-level table (see Section 6.6.3). [This approach was informed by the NTP Cancer Assessment of Night Shift Work and Light at Night (NTP 2021a)]. The evaluation protocol would provide more specific guidance.

### 6.4.2 Step 1: Assess the Evidence for Each Study Set: Biological Effects

Study sets for each influential mechanistic question, defined by the EECO statement, can also include intermediates that be considered as exposure, and includes many different types of endpoints (e.g., KCC or other intermediates). Night shift work represents a complex data set in which circadian disruption (a key intermediate) can be viewed as an exposure or an outcome in evaluating exposure-outcome associations.

The depth of the assessment of the individual studies depends on the influential literature analysis. Some evidence may be reported from review articles, others at a high level (streamlined extraction) using Tableau or other visualizing tools, while an in-depth assessment will be conducted on the most influential literature. If relevant, a meta-analysis or other quantitative methods can be used to explore heterogeneity, bias, and other key issues in the literature within an evidence stream (e.g., human studies). Additionally, forest plots or other graphical methods stratified by study or other characteristics may be useful in exploring heterogeneity without a quantitative analysis. Meta-regression or other analytical methods could be used to evaluate dose-response relations across studies to support the strength of the evidence. Because of variability in how studies are conducted, and the types of exposure and outcomes reported, it may be difficult or inappropriate to combine studies in a meta-analysis (see Section 3.3.2 for a discussion on strengths and limitations of using meta-analysis in a hazard assessment).

The assessment considers the following factors:

- Consistency of the evidence across studies
  - Assessment of the evidence for a specific KCC from individual studies may integrate the findings of multiple biomarkers or indicators for that effect (e.g., a study-specific assessment of chronic inflammation may include results for proinflammatory cytokines and lymphocyte subsets). We used the term indicators for effects that are not biomarkers per se, such as outcomes (e.g., increased infection for immunosuppression, histopathology, or organ weights).
  - Each KCC-specific biomarker or indicator (e.g., increases or decreases in lymphocytes) may be integrated across the study set.
- Strength of the association, such as magnitude of the effect and exposure-response relationships, and uncertainty
- Study informativeness (e.g., internal validity, sensitivity)
  - Tissue/sample (e.g., local, target tissue, or circulation). In general, evidence for KCC biomarkers in target tissues is more informative than circulating/systemic biomarkers, although it may depend on the KCC and cancer site of interest.
  - Relevance (e.g., duration, dose, timing) of the exposure and measurement of the biological effect.
- The assessment uses a triangulation approach, which integrates evidence from different study designs and methods, as well as different sources of potential biases, to reach conclusions about consistency.

Each evidence-based table captures the integration of the evidence for each study set, the strength and limitations identified by the informativeness evaluation, and the overall assessment (see Section 6.6.2).

### 6.4.3 Step 2a: Assess the Confidence of the Evidence: Biological Effects

For each influential question, we integrate the assessments across study sets, using triangulation approaches across the mechanistic evidence, to reach a confidence judgment based on the guidance outline in Table 6-13 and discussed below. Key considerations are the consistency and cohesiveness of both the effect and the biomarkers used to measure an effect/KCC, the overall quality of the collective evidence across study sets, and the informativeness of the biomarkers. For most evaluations, a biological effect is one of the KCCs (recognizing that some KCCs have multiple effects); thus, our focus in this handbook is on KCCs. However, this is not a strict requirement, and KCCs may be refined over time, or new biological effects may be identified.

Table 6-13 Confidence Judgment for Biological Effects

Descriptor | Biological Effect
High | Individual biological effect (KCC) Consistent evidence of informative KCC biomarkers/indicators^b^ across studies of sufficient quality and ideally in more than one evidence type Coherence across individual KCC biomarkers/indicators Relationships between KCCs or multiomic data Consistent evidence across studies for an association between two or more biological effect biomarkers/indicators
Moderate/Limited | Less than consistent evidence across studies, KCC biomarkers/indicators, and evidence types Consistent evidence for less relevant KCC biomarkers/indicators or less biological or human-relevant evidence^a^ types, or few studies (e.g., limited ability to evaluate consistency)
Inadequate | Negative or unexplained inconsistent findings Few data or limited study informativeness Evidence mainly from evidence types with low biological or human relevance for the substance and specific biological effect under evaluation^a^ KCC biomarkers/indicators are of limited informativeness for the biological effect and cancer development

^a^ Biological and human relevance are evaluated on a case-by-case basis, e.g., some nonmammalian in vivo assays may be relevant for some but not other KCCs, and some species may be more relevant than others.

^b^ Indicators are defined as effects that are not biomarkers per se, such as outcomes (e.g., increased infection for immunosuppression, histopathology, or organ weights).

#### Informativeness of the Study Set

The informativeness of the study set considers the quality of the study set as a whole, including the evidence type, the adequacy of the exposure proxy, and informativeness of the indicators or biomarkers for measuring the biological effect. Our evaluation uses a triangulation approach that considers the source of collective bias and whether the evidence points to the same conclusions. Ideally, the evidence should come from biological (e.g., exposed animals) and human-relevant studies (exposed humans and human cells); however, each evidence type is associated with different types of potential biases: Human epidemiology studies may be at risk from confounding or exposure measurement error, in vivo experimental studies may have species-specific issues, and human in vitro studies are limited by the physiological relevance to model tissue function (such as inadequate metabolism of the substance to the carcinogenic species or ADME effects that may decrease the delivered dose). Despite these biases, all evidence types can contribute to the evaluation, and consistent findings across evidence types increase the confidence of the evidence conclusion. In cases for which there is heterogenicity across evidence types, substance- and evaluation-specific issues (such as study quality and bias for a particular evidence stream) will be used to consider which evidence type(s) are most informative. A separate confidence call (i.e., robust) is made for studies in exposed humans to facilitate overall evidence integration (human cancer studies, animal cancer studies, and mechanistic studies; see Section 7). Robust means that there is consistent evidence across studies for an informative KCC, which is usually supported by experimental evidence. Studies from all evidence types are not needed to make conclusions.

The exposure proxy (if relevant) for a study set should be adequate for the exposure of interest (see Section 3.2.2, Table 3-4). For example, a question in the antimony trioxide assessment was whether other antimony trivalent compounds were appropriate for evaluating the effects of antimony trioxide. A question in the night shift work assessment was whether differences in the timing of simulated night shift work in experimental studies captured the “real-world” exposures of night shift work.

The KCC biomarkers and indicators should be informative for assessing the KCC. Table 6-14 provides guidance to reach high confidence for the KCCs, and Appendix D provides background information on KCC biomarkers and indicators. Each KCC consists of several subtypes measured by different biomarkers or indicators (see Appendix D tables). For example, the main subtypes of oxidative stress include reactive oxygen species (ROS), ROS modifications to DNA, RNA, protein or lipids, and antioxidants. High confidence for some KCCs (e.g., oxidative stress or chronic inflammation) is reached by integrating across the subtypes, whereas, for other KCCs (such as genotoxicity), evidence for only one subtype (e.g., strong evidence for mutagenicity and negative for chromosomal damage) is sufficient for a high confidence judgment. KCC 10 encompasses several biological effects, each of which can be evaluated independently.

When assessing the relationship between KCCs, we consider consistency across studies and evidence types, dose/response, timing, or sequence of events. Assessing the confidence of biological effects may lead to new mechanistic hypotheses for the substance under evaluation. (These questions differ from influential questions that are for MoA that have been in the literature during the scoping process and are discussed in the next section.) For example, in the RoC review of haloacetic acids found as water disinfection by-products, assessment of the evidence for KCCs led to several proposed mechanisms, suggesting that cancer-initiating events involve electrophilic reactions with proteins and MoA involving oxidative stress resulting in mutations and chronic inflammation and epigenetic changes leading to altered gene expression and DNA repair (Atwood et al. 2019), all of which can lead to cellular proliferation, transformation, and cancer. Proposed biological pathways or MoA (e.g., timing/steps) may be based on actual studies or general knowledge about carcinogenicity. However, the associations between the substance and specific biological changes could reflect the availability of studies and not the level of its contribution to carcinogenicity (Atwood et al. 2019; NTP 2018a; 2018b).

Table 6-14 Informativeness of Key Characteristic of Carcinogens Biomarkers or Indicators

KCC | Ideal Evidence for High Confidence | Other Evidence for High Confidence: Combination of Biomarkers/Indicators^a^ | Biomarkers/Indicators and Cancer Prediction
KCC1: Is electrophilic or can be metabolically activated to electrophiles | Covalent DNA adducts in target tissues DNA adducts with higher “hardness” are more relevant for cancer development as they are less likely to be repaired (e.g., O^6^ adducts are more informative than N^7^ adducts) | Covalent DNA adducts in nontarget tissues Protein adducts; RNA adducts Electrophilic properties, such as potency, measured in vitro or in silico Evidence of electrophilic chemical structure of metabolite or primary chemical | High levels of specific chemical or bulky DNA adducts have been associated with increased risk of several types of cancer (e.g., colon, liver, lung in smokers, prostate, stomach) in prospective studies, albeit the risk estimate may be due to exposure to the substance as adducts are also biomarkers of exposure.
KCC2: Is genotoxic | Positive findings for ≥1 endpoint in exposed animals or humans • Mutations • Chromosomal damage: CA or MN (indicative of CA and changes in chromosome number) | DNA damage: strand breaks in target tissues of exposed humans or animals Mutations or chromosomal damage: in vitro studies using bacteria or eukaryotic cells | MN and CA associated with increased cancer risk in prospective cohort studies. Chemical-specific mutational spectra observed in cancers. Ames-positive chemicals (and chemicals positive for several in vitro mutagenicity assays) and in vivo MN are strong predictors of carcinogenicity.
KCC3: Alters DNA repair (DRC) or causes genomic instability | Direct (e.g., not due to secondary effects) evidence of impaired DRC from the comet DNA repair assays or γH2AX assay Direct evidence of exposure-induced genomic instability (e.g., ideally in nontumor tissue) | Several biomarkers with less specific evidence (Topoisomerases), and relevant biomarkers from other KCCs (e.g., changes in telomere length) | Lower DRC linked to increased cancer risk for combined cancers and several specific cancer types (meta-analyses) using various assays. Most genomic instability assays have been done on tumor cells.
KCC4: Induces epigenetic alterations | DNA methylation in epigenetic clock genes or relevant cancer-related genes OR Epigenetic changes (histone modification, DNA methylation not related to epigenetic clock, and noncoding RNA) in combination with downstream effects (e.g., transcription) | Histone modification Noncoding RNA Global methylation | Accelerated epigenetic aging is associated with an increased risk of cancer development.
KCC5: Induces oxidative stress | Several oxidative stress biomarkers (pro- and antioxidative stress) • Integrative score • Pro-and antioxidative stress biomarkers in the same studies | One or more clinically relevant oxidative stress biomarkers, such as F2-isoP and oxidative damage to DNA And Link with other KCCs (e.g., KCC2, KCC6) | Higher levels of 8-OH-dG, hOGG1 (tissue), MDA, or protein carbonyls have been found in urine, tissue, or blood of cancer (urinary bladder, breast, cervical, liver) patients than controls. Studies of oxidative stress biomarkers and cancer risk are limited or unclear.
KCC6: Induces chronic inflammation or immune activation^b^ | Evidence of chronic inflammatory (e.g., autoimmune) diseases in exposed humans or animals Histological evidence of chronic cellular inflammation in target tissues (WBC- e.g., lymphocytes) with local increases in proinflammatory biomarkers (e.g., specific cytokines or chemokines) in exposed humans or animals • Ideally, the biomarkers are associated with cancer and are identified in the context of evidence of chronic exposure (or repeated acute exposures) | Histological evidence of chronic cellular inflammation in nontarget tissues with local increases in proinflammatory biomarkers in exposed humans or animals Systemic increases in acute (with evidence of chronic exposure) or chronic inflammatory cells or proinflammatory biomarkers (e.g., cytokines, chemokines, or acute phase proteins) in circulation • Ideally, the biomarkers are associated with cancer and are identified in the context of evidence of chronic exposure (or repeated acute exposures) • Systematic inflammation may be more informative for blood cancers compared to solid tumors | Pre-diagnosis of increased IL-6, IL-8, CRP, SAA, and WBC associated with increased risk for several types of cancers.
KCC7: Is immunosuppressive | Evidence of increased viral infections in exposed humans or animals Impaired immune function, such as decreased antibody responses, NK, CTL, and T cell activation/activity in exposed humans or animals | Evidence of increased nonviral infections in exposed humans or animals and supporting evidence (e.g., alterations in immune components or organs) Severe decreases in WBC/leukocyte subsets and supporting evidence (e.g., decreased cytokines)
KCC8: Modulates receptor-mediated effects | Direct receptor-mediated binding and transactivation (with effects on gene expression) | Indirect modulation of receptor effects Increased levels of endogenous hormones Overexpression of receptors for hormone sensitivity | ER-, PR-, AR-, AHR-mediated transactivation has been associated with cancer risk. Increased levels of endogenous estrogens, androgens, and thyroid hormones have been associated with cancer risk. Estrogen alone or estrogen-progesterone menopausal therapy and estrogen-progesterone oral contraceptives are known human carcinogens.
KCC9: Causes immortalization | Cell transformation as observed via (1) anchorage independence and loss of contact inhibition (foci formation), (2) de-differentiation, or (3) evidence of invasiveness • Inactivation of tumor suppressor genes or activation of oncogenes increases confidence. Increased telomerase activity in exposed humans or animals | Change in telomere length Inhibition of cellular senescence (assessed by multiple biomarkers) | Formation of cell foci has high concordance with cancer risk in rodents. Increased telomerase activity is a risk factor for cancer.
KCC10^c^: Alters cell proliferation, cell death, or nutrient supply (e.g., angiogenesis) | Hyperplasia or increased DNA synthesis during S-phase Increased pathogenic (sustained) angiogenesis and neoangiogenesis Glycolytic shift in exposed animals | Resistance to apoptotic cell death and other biomarkers of cellular proliferation | KCC represents multiple biomarkers, many of which are for tumor promotion or malignancy progression. Usually considered a consequence of cancer but may also be a cause of cancer.

Source (including citations): Appendix D and Smith et al. (2020).

8-OH-dG = 8-oxoguanine DNA glycosylase; AHR = aryl hydrocarbon receptor; AR = androgen; CA = chromosomal aberration; CTL = cytotoxic T lymphocyte; DNA = deoxyribonucleic acid; DRC = DNA repair capacity; ER = estrogen; h0GG1 = human 8-oxoguanine glycosylase-1; IL = interleukin; KCC = key characteristics of carcinogenicity; MDA = malondialdehyde; MN = micronucleus; NK = natural killer cells; PR = progesterone; RNA = ribonucleic acid; SAA = serum amyloid A; WBC = white blood cells.

^a^ In the absence of studies on the ideal biomarkers/indicators, evidence from multiple biomarkers/indicators could be used to reach high confidence. We used the term indicators for effects that are not biomarkers per se, such as outcomes (e.g., increased infection for immunosuppression, histopathology, or organ weights).

^b^ Not defined as a KCC by Smith et al. (2020); however, dysregulation/persistent immune activation (such as B-cell antigen activation) can contribute to the development and progression of cancer. The concept of immunomodulation is part of the 2015 Handbook, as recommended by the peer reviewers of that Handbook. See Appendix D for more details.

^c^ Primarily from Smith et al. (2020). This will be updated as part of updates to the living document and could be considered multiple KCCs.

### 6.4.4 Step 2b: Assess the Confidence of the Evidence: Mode of Action and Adverse Outcome Pathway

MoA/AOP (or other biological pathway)-related influential questions are identified after broad literature searches and are unlikely to be the only questions for an evaluation. Confidence judgment is reached by assessing (1) the confidence that the substance causes the predominant biological effects in the proposed MoA/AOP or pathway (e.g., molecular initiating event or several key events) (direction provided in Section 6.4.2, Step 1 above) and (2) how well the data for the substance fit the proposed MoA (see Table 6-15). To illustrate the evaluation process, we discuss two exemplars of RoC-listed substances.

Table 6-15 Confidence Judgment for Mode of Action or Adverse Outcome Pathway

Descriptor | MoA
High | High/moderate confidence that the substance causes the key biological events in the proposed MoA The evidence is a “good fit” for the proposed MoA as demonstrated by: • High confidence for the most critical biological events in the MoA • The biomarker used to measure the specific biological event is the most relevant for the MoA • The sequence/timing and dose/response of events (e.g., semiquantitative) relative to each other and tumor formation are consistent with the proposed MoA
Moderate/Limited | High confidence that the substance causes an event in the proposed MoA, but the evidence is a moderate fit for the proposed MoA Moderate confidence for several key events in the MoA and moderate confidence for a good fit to the MoA
Inadequate | Inadequate confidence for several key events in the MoA

#### Exemplar: Cumene and Male Rat Kidney Tumors

For the cumene evaluation, a key question was whether the chemical causes renal tumors in male rats by an MoA that is considered not to be relevant to humans (i.e., alpha(2u)-globulin nephropathy). To answer this question, an information group applied criteria consisting of seven factors for 2u-globulin-associated nephropathy (IARC 1999) to the relevant data from cumene toxicity and other studies. The overall conclusion was that cumene exposure induces 2u-globulin-associated nephropathy in male rats; however, it is unclear whether other mechanisms may play a role in carcinogenicity. Not all the specific 2u-globulin-associated nephropathy factors were fulfilled. Cumene is listed as reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from animal studies, i.e., it causes lung and liver tumors in mice; kidney tumors in male rats provide supporting evidence (NTP 2013; 2021d).

#### Exemplar: Trichloroethylene and Non-Hodgkin’s Lymphoma

For the TCE evaluation (NTP 2015), a key question was whether the available TCE immune studies supported a B-cell activation MoA leading to somatic hypermutation, proliferation of mutated B cells, and lymphoma. The information group concluded that although trichloroethylene or its metabolites can cause both immunosuppression and autoimmunity in humans and animals, the available studies in humans and animals measuring immune function were not entirely consistent with this hypothesis. If there was more convincing evidence for this MoA, the collective LoE from studies in humans (human cancer epidemiological and mechanistic studies) might have been sufficient rather than limited (the evidence from human epidemiological studies was limited). Although this evaluation was prior to the 2016 publication on KCCs, conclusions of high confidence for chronic inflammation or immunosuppression may not have translated into an “upgrade” for a cancer-specific LoE conclusion.

### 6.4.5 Step 3: Assessing the Level of Evidence

The LoE conclusion of carcinogenicity from mechanistic evidence is reached by applying the RoC listing criteria to the body of literature. The final step integrates the confidence judgments across the influential mechanistic questions (Step 2) and considers the cohesiveness of the database to reach a conclusion for one or more LoE questions (Q1 to Q3, see Table 6-16). Each substance evaluation will have several questions, some of which may overlap. For example, evaluating the confidence for a read-across prediction includes assessing the evidence for an MoA as part of its uncertainty analysis (see Section 6.5.2). The review also summarizes the data that was not considered to be influential. The LoE of carcinogenicity from mechanistic studies is integrated with the LoE of carcinogenicity from cancer studies in humans and animals to reach a cancer hazard conclusion (i.e., listing recommendation) (see Section 7).

Considerations for reaching LoE conclusions are discussed below and summarized in Table 6-16, organized by the different LoE questions (see Section 6.1) and the strategies for evaluating those questions. For comprehensiveness, the table (but not the text) also includes read-across and clustering-related questions, which are discussed in Section 6.5.2.

#### Consideration of All Information

The RoC listing criteria note that cancer hazard conclusions (e.g., listing recommendations for known or reasonably anticipated to be a human carcinogen) “are based on scientific judgment with consideration given to all relevant information.” These considerations can occur during the assessment of mechanistic evidence or overall cancer hazard evaluation (e.g., evidence integration of human and animal cancer and mechanistic studies; see Section 7). Examples of relevant information include mechanistic data (e.g., biological effects and mechanisms of action) and information related to ADME and toxicokinetics, which can potentially modify a mechanism. For hazard identification, qualitative (or very extreme quantitative) species differences are most relevant. Information on ADME and toxicokinetic/toxicodynamic data can be considered at all three steps in the process: evaluating individual studies or uncertainty in read-across approaches (Step 1), integration across study sets and the confidence judgments for biological pathways/MoA (Step 2), and as part of biological coherence in reaching an LoE conclusion (Step 3).

Substances often cause cancer via their metabolites, and metabolism data may be reviewed at multiple levels, e.g., electrophilicity is a KCC (and can be related to other KCCs), and metabolism to a reactive species could be a key event in an MoA or a part of read-across analyses. The RoC lists chemicals (or classes of chemicals) based on their metabolism to a human or animal carcinogen (e.g., dyes metabolized to benzidine). In these cases, the ADME evaluation (see Section 5) would assess the extent and the nature of the metabolism to the carcinogen, e.g., the amount of metabolite produced, the likelihood the metabolic pathways occur in humans, and data on whether the target chemical metabolism results in the proximate metabolites of the carcinogen. The overall cancer hazard evaluation (Section 7) integrates the metabolic and relevant mechanistic information with cancer data for the metabolite to reach a listing recommendation.

#### Biological Effects (KCCs): LoE Q1

Assessing the LoE of mechanistic data based on biological KCCs considers many factors. Although the KCCs, by definition, are properties of carcinogens, they are not necessarily specific to a cancer type, and other adverse health effects share some of these KCCs. Thus, in the absence of other supporting data, high confidence for a single informative KCC is typically not enough to reach convincing mechanistic evidence for cancer causation but may be adequate for supporting evidence. Mechanistic understanding of a substance must be compelling to list a substance with inadequate or limited cancer data. For substances that meet the RoC criteria for listing based on human or animal cancer studies, high confidence for a biological effect for most KCCs may be sufficient to support a moderate LoE from mechanistic studies. Scientific judgment and assessing the coherence of the database are critical for the assessment.

##### The number, connections, and specificity of the KCCs or other biological effects

A given evaluation may evaluate the evidence for several biological effects, usually KCCs. Information on connections, sequence, and timing of several KCCs may help identify substance-specific biological pathways and increase the certainty of the evidence. The specificity of the KCC toward cancer also contributes to the LoE conclusion as many KCCs are important in nonmalignant disease. Specificity for cancer (e.g., some KCCs are also characteristics of noncancer toxicants) varies across KCCs and may depend on the chemical. For example, inducing oxidative stress and chronic inflammation are less specific for cancer whereas causing immortalization has higher specificity; most others KCCs are in a continuum between these examples.

In addition to considering the specificity of the KCC, the informativeness of the specific biomarker (or several biomarkers) used to measure the KCC is paramount. We evaluate this at all three steps in the process with increasing stringency. For high confidence in biological effects, the biomarker should be highly relevant for the KCC (e.g., mutation, chromosomal damage), and for convincing LoE, it should also predict cancer. For the latter decision, supporting cancer data or strong evidence establishing a cancer mechanism is needed.

##### Supporting cancer data

In addition to informing the overall cancer hazard evaluation, cancer studies in humans and animals can inform the assessment of mechanistic evidence, such as providing information on the cancer site. Even cancer data not meeting the RoC listing criteria can inform the evaluation of mechanisms. For instance, data on a cancer site may be based on an animal database consisting of a single treatment-related tumor site in one species or a human database of a few studies suggesting a link with a specific type of cancer.

To demonstrate that a specific biomarker predicts cancer or is involved in tumor formation, we ideally would have data that suppression of an adverse biological effect led to suppression of tumor development. For example, a series of studies using different designs of simulated light at night (LAN) in experimental animals demonstrated that exposure to LAN suppresses melatonin (which is protective of cancer) and low melatonin was associated with breast (human implant studies) or mammary tumor progression (NTP 2021a). Cancer studies measuring KCCs in the same study can also help establish a link between KCCs and substance-specific cancer mechanisms as illustrated in the night shift work evaluation: Several KCCs found in night shift workers were the same as those detected in the animal cancer studies in which animals were exposed to simulated night shift work or jet lag using changes in light patterns (NTP 2021a). Meet-in-the-middle approaches—linking a biomarker (e.g., metabolomics) to both exposure and disease using a prospective epidemiological study design—can also provide evidence of a cancer link in these studies (Chadeau-Hyam et al. 2011). As multiomic approaches advance, these studies may play a greater role in future evaluations. Overall cohesiveness and concordance between a cancer type and the KCC may strengthen the informativeness of the KCCs or other biomarkers.

#### Biological Pathways/MoA: LoE Q2 and Q3

Typically, these influential mechanistic questions are for cancer site-specific MoA related to biological plausibility or an AOP for an established cancer pathway. LoE conclusions may be cancer site-specific and integrated with human and animal LoE for a specific cancer site in the overall evaluation (see Section 7). Compelling evidence for nonrelevance in humans is needed to discount strong evidence of carcinogenicity from studies in experimental animals. “Compelling” is defined as high confidence for MoA/AOP with scientific consensus that it would not occur in humans, inadequate human cancer data (at any site), and inadequate human-relevant biological effects in the target tissue. Other MoA (Q2) provide evidence of biological plausibility and may be for a specific cancer site (such as those observed in humans) or cancer site agnostic. In general, the confidence judgment for the MoA translates to the LoE conclusion of carcinogenicity of a substance from mechanistic studies (e.g., high confidence to convincing evidence, moderate confidence to supporting evidence).

Table 6-16 Level-of-evidence Guidelines

RoC Criterion | Convincing | Supporting
Q1. Plausibility: Biological effects KCC or other relevant effects, including metabolism Connectivity between KCCs | Coherence in the database (including mechanistic data, toxicokinetics) AND High confidence for one or more informative biological effects considering the following^a^: • Number, sequence, connections between KCCs leading to the development of a biological pathway • Specificity and informativeness of KCC biomarkers • Supporting cancer-related data • Suppression of biological effect led to suppression of tumor development • Biological effect measured in cancer studies (typically in vivo) exposed to the substance • Measured in target or cancer site of interest | High or moderate confidence for informative KCCs • If the confidence judgment for KCC is moderate confidence, a greater number and specificity of the KCC is needed • If the confidence judgment is high, a single specific KCC or several less specific KCCs would meet the requirement
Q1: Plausibility: Reported biological pathway/MoA | High confidence for an MoA that is for one of the following: • Cancer site observed in humans or experimental animals • Established cancer pathway | Moderate confidence for an MoA or AOP
Q1 Plausibility: Predicted to cause cancer^b^ Q2: Member of a listed class Clustering and read-across approaches | High confidence for read-across/clustering • Low uncertainty encompasses evaluation of MoA for the source chemicals and biological effects of predicted chemicals^d^ | Not relevant^c^
Q3. Not relevant to humans/MoA (Compelling) | High confidence for an MoA for a cancer site observed in animal studies Strong scientific consensus that the MoA is not relevant to humans Low confidence for KCCs in the target tissue Inadequate^e^ mechanistic data in exposed humans | Not relevant^c^

^a^ Scientific judgment is used to integrate the issues in the bullet, and not all are required

^b^ See Section 6.5.

^c^ “Supporting” is not relevant because these questions are for when there is not an adequate database from human or animal cancer studies, or the evidence is downgrading the studies in experimental animals.

^d^ Source chemicals are associated with tumors in experimental animals and possibly in humans and can be listed or nonlisted substances.

^e^ “Inadequate” means that either no human data are available or no data in humans supporting biological plausibility are available.

## 6.5 Read-across Approaches

Because read-across approaches for cancer hazard evaluations are continuously advancing and are evaluation specific, the substance(s) evaluation protocol can more accurately capture the state of the science on read-across approaches than the handbook. The handbook provides high-level concepts for scoping, developing a protocol and evaluating read-across approaches. As a living document, we will update the handbook to reflect advancements in knowledge and technology.

### 6.5.1 Identification of Read-Across as an Influential Question

As discussed in Section 1, substances are selected for review for the RoC based on initial scoping and problem formulation activities. During this process, substances with cancer data may lead to expanding the scope to evaluate a potential class, subclasses or structurally related chemicals. These chemicals may (e.g., nitro-polycyclic aromatic hydrocarbons (https://ntp.niehs.nih.gov/whatwestudy/assessments/cancer/ongoing/npah)) or may not (haloacetic acids (https://ntp.niehs.nih.gov/publications/roc/rocmgraph12) found as drinking water contaminants, halogenated organic flame retardants (https://ntp.niehs.nih.gov/whatwestudy/assessments/cancer/ongoing/hfr)) be related to substances listed in the RoC (Lunn et al. 2022).

Using the methods outline in Section 6.2, RoC staff conduct scoping and problem formulation activities to identify influential questions: scientific issues that will most likely impact the LoE conclusions. If read-across is identified as influential questions for substances with limited human and animal cancer data and that share similarity with substances with cancer data, we search the literature (using the methods outline in Section 6.2) for published or validated read-across approaches (e.g., analogue or category). If found, the evaluation team may consult with technical advisors to assess its quality and will summarize the analyses in the protocol. If there are no published read-across methods or analyses for carcinogenicity, RoC will conduct further scoping activities to develop a read-across framework (Section 6.5.2).

### 6.5.2 Read-across Framework Development

Scoping activities for read-across approaches are complex and involve preliminary analyses in addition to information searches (see Section 6.2 for methods for identifying and mapping studies and data) to develop the read-across framework, including the read-across hypothesis and argumentation, the definition of analogues (source and target chemicals), and approach. A series of iterative questions, including questions about the source of uncertainty (Schultz et al. 2015; Schultz et al. 2019) and workflows developed by others (e.g., Ball et al. 2016; OECD 2023b; Patlewicz et al. 2015; Patlewicz et al. 2017), guide the process.

Key events (AOP) or key intermediate steps (MoA) represent a sequence of biologically relevant multiple steps leading to carcinogenicity. Hence, reviewing the quality/informativeness of carcinogenicity studies in humans and/or experimental animals and assessing mechanistic evidence for the source chemicals are critical to evaluate the feasibility of using read-across (see Section 6.5.3). Importantly, the selection of the final list of analogues for read-across ascertains relevant features, such as physical-chemical properties, toxicokinetic-related properties (e.g., bioavailability, metabolism, and degradation pathways), and toxicodynamic properties of chemicals with an emphasis on MoA. Thus, we will also consider endpoint-specific (carcinogenicity and intermediate endpoints) parameters, properties, and chemical biological predictive data beyond 2-D. This will expand the definition of structural for biological similarity and provide a different critical context for analogue selection. This is also intended to create a transparent rationale that supports the selected read-across analogue(s) for the specific endpoint under study (Lester et al. 2023; Moustakas et al. 2022). Analogue selection is discussed further below.

For the purpose of the handbook, we provide general concepts and activities, rather than specific workflows, for scoping and developing a read-across framework plan (see Blackburn and Stuard 2014; ECHA 2017; 2023; Myatt et al. 2018; OECD 2023a; Patlewicz et al. 2018) for more information on read-across tools, flowcharts, and other methods. Given the broad range of complexity and diversity of substances selected for review and the limited, if any, case studies of read-across analysis for cancer, we feel this is appropriate.

#### Read-Across Purpose

Our read-across predictions require low uncertainty for the cancer prediction and incorporation of biological effects into the model as their purpose is to list or not list substance in the RoC, a public health congressionally mandated document.

#### Identifying the Sources and Negatives

During the scoping activities (see Section 6.2), we search for and extract the findings of the available cancer studies in exposed humans and experimental animals to identify potential positive (sources) and negative chemicals to be proposed in the read-across plan. The quality of the endpoint or outcome data (e.g., cancer) provides one of the fundamental sources of uncertainty in a read-across strategy. Data with low uncertainty are sought, which may include aspects of the reliability of the data, relevance and specificity to the endpoint of carcinogenicity in exposed humans and experimental animals, as well for human health/environmental effects (Schultz et al. 2019). The final study informativeness and cancer hazard assessment, following the systematic review and evidence integration methods outlined in Sections 3 and 4, informs the uncertainty analysis (see Table 6-17).

#### Assessing the Mechanistic Evidence and Developing the Read-Across Argumentation

The read-across argumentation encompasses the justification for using read-across based on a developed mechanistic hypothesis. Substantial scoping of mechanistic studies of the source chemicals are done to identify proposed mechanistic frameworks (e.g., MoA, AOP, molecular pathways, metabolism). The read-across hypothesis is based on an identified common biological framework (e.g., the molecular initiating event [MIE] and one or more key events that lead to carcinogenicity). The applicability domain is the chemical, biological, toxicodynamic, or toxicokinetic properties required to identify analogues for read-across (Pestana et al. 2022). Biological, chemical and toxicokinetic similarity, often based on the MoA for cancer, across source chemicals is key to defining the applicability domain. The overall mechanistic assessment will evaluate the confidence in the proposed MoA or biological effects (see Section 6.4), which is an uncertainty factor for read-across (see Table 6-17).

Key descriptors, including properties and parameters of source chemicals related to the MIE and intermediate endpoints, are identified and used to create a data matrix (see Section 6.6.1) for the source chemicals and potential negatives if available. These descriptors may include structures and functional groups, or parameters such as molecular surfaces and volumes, data on relevant chemical biology interactions, ADME properties, or biological activity. Data and descriptors on carcinogenicity and intermediate endpoints can be found in the literature, or from data repositories, or may be calculated. Preliminary examination of the sources (category or not) and available potential negatives can also help deciding which descriptors are more indicative and predictive to discriminate active from inactive substances.

#### Selecting and Evaluating the Final List of Analogues, Data Matrix and Requirements

Sources and negatives are initially identified through scoping activities from available cancer studies in exposed humans and experimental animals based on the substance under review (discussed above). The final selection of the analogue sources, or clusters of analogue sources, may be redefined with new ones added which may extend outside the chemical class under review and others removed if they are not endpoint specific, based on the assessed mechanistic evidence and developed read-across argumentation (e.g., similar MoA, toxicokinetics), and on the defined appliability domain. We will use authoritative reviews, national and international chemical information and data repositories many of which can be found in the list of general sources in Appendix B (e.g., EPA CompTox Chemicals Dashboard (https://comptox.epa.gov/dashboard/), NTP Integrated Chemical Environment (https://ice.ntp.niehs.nih.gov/), OECD eChemPortal (https://www.oecd.org/chemicalsafety/risk-assessment/echemportalglobalportaltoinformationonchemicalsubstances.htm), ECHA REACH (https://echa.europa.eu/regulations/reach/understanding-reach)) to identify analogue candidates for read-across within and outside the chemical class under review (Moustakas et al. 2022). To select the final list of analogues, a supervised approach that is based on selected endpoint-specific parameters, properties, predictive data beyond 2-D (for both carcinogenicity and intermediate endpoints) will be used. Target chemicals are analogues that are not sources or potential negatives. The data matrix is expanded to include the identified descriptors for the target chemicals. Like sources, properties, parameters, predictive data for the target chemicals found in literature, data repositories, or calcuated can be evaluated. The data matrix will identify data rich and data poor targets, the most studied biological effects, ADME, and how well the available data align with the proposed MoA or AOP. Other searches are related to the quality and quantity (i.e., availability) of data for read-across. Data for the data matrix will come from authoritative source (e.g., EPA’s CompTox or LeadScope), and will be supplemented with data from primary studies as needed. The data will be evaluated for study informativeness using the methods outlined in Section 6.3.

As part of the evaluation of the final list of analogues, the similarity between targets and sources and fit between the applicability domain is determined using the data collected in the matrix. We also reevaluate the read-across argumentation to determine whether a read-across approach is feasible and to decide which approach (analogue or category) would be used (Patlewicz et al. 2018; Schultz et al. 2019).

#### Uncertainty Assessment

We assess uncertainty from several sources or types per source—including cancer data for source chemicals, biological plausibility, and similarity justification. These uncertainty sources are part of the pre-read-across implementation during scoping (Table 6-17, Section 6.5.3) and are integrated with other uncertainty types (from the read-across analysis, see Table 6-17) to reach an overall judgment (see Table 6-18, Section 6.5.3). Importantly, we would only develop a read-across plan when we are confident in these factors (Schultz et al. 2019).

#### Protocol Development

Informed by scoping activities, the protocol will provide the read-across hypothesis and elements in the prioritized read-across plan (see Box 6-5 for examples). Critically, a hypothesis stating the chemical and biological mechanisms underpinning the carcinogenic effect for reading across the candidate substance or group of related substances is needed. Ideally, it will also include alternative plans (e.g., changing from category to an analogue approach, computational to a qualitative noncomputational approach, or adding new chemicals from animal evidence only) if the prioritized plan does not work. For published read-across analyses, the protocol will provide the same information as above and an assessment of the rationale and quality of reported read-across methods.

Box 6-5 Read-Across Plan Elements

Definition and members of the category, including source and target chemicals

Scoping activities and analyses summary

- Biological and chemical evidence maps for the chemicals
- Specific criteria for analogue selection
- Similarity justification of target and source chemicals
- Preliminary assessment of human and animal cancer (e.g., animal cancer data)

Framework, read-across methods

- Read-across argumentation
- Type of approach: category or analogue
- Descriptors, parameters, properties
- Data matrix template and types of input data
- In silico quantitative prediction and clustering methods, classification, visualization, statistical analysis, tools

Considerations to evaluate uncertainty

### 6.5.3 Evidence Evaluation and Integration

Evaluation of the confidence of the read-across prediction for each target chemical (or class of chemicals) considers the strength (e.g., scientific judgment, correlation, nearest neighbor) of the similarity between the target and source chemicals and for those targets with high and moderate prediction, assessing the uncertainty associated with the cancer prediction and read-across process (Schultz et al. 2015). The evaluation may be of a reported read-across/clustering analysis or a new model conducted for the RoC evaluation. For RoC evaluations, first, we rate each uncertainty type (Step 1) and then integrate the ratings across types to reach an overall judgment (Step 2). The confidence judgment for the cancer prediction is integrated with other evidence to reach a level-of-evidence conclusion (Step 3) (see Box 6-6).

#### Step 1: Rating Uncertainty

Box 6-6 Evidence Integration for Read-Across

Among the many resources for evaluating uncertainty, our evaluation adapts a series of questions proposed by Schultz et al. (2019) for each type and source of uncertainty. Uncertainty types or questions are organized by the read-across process (see Table 6-17) and linked to their source(s): (1) quality of the cancer data for the sources, (2) read-across argumentation, and (3) similarity justification. Read-across argumentation refers to the plausibility of the cancer mechanisms and the completeness, quality, and robustness of the supporting evidence. Similarity justification refers to the similarity (chemical structure, physio-chemical properties, toxicodynamics, and toxicokinetics) between the source and target chemicals. Some uncertainty types are from more than one source.

Table 6-17 provides information—source, evidence base (e.g., study sets, data), and considerations (derived from questions)—for eight uncertainty types, organized by process step. Each uncertainty type (minor, moderate, or major) is rated using scientific judgment and, for some cases, based on conclusions reached for other parts of the evaluation (e.g., confidence conclusions for MoA, biological effects, or LoE of carcinogenicity from animal studies).

Table 6-17 Types and Sources of Uncertainty in the Read-across Analyses for Each Target Chemical

Type^a^ | Source | Process Step | Evidence or Data | Considerations
1. Definition and grouping of chemicals as analogues or as a category | Read-across Argumentation Similarity justification | Pre-read-across implementation | Data matrix tables and evidence maps: Physio-chemical properties, mechanistic data | Targets and source chemicals are clearly defined and fit with in the applicability domain
2. Quality of the cancer data for the sources | Source chemicals | Pre-read-across implementation (preliminary) Cancer hazard evaluation (final) | Assessment and conclusions from human and animal cancer studies^b^ | LoE conclusions from human and animal cancer studies including study informativeness (bias and study sensitivity) and evidence for tumor formation for source chemicals Presence of presumed negatives control • Study sensitivity for reported negative findings
3. Biological plausibility | Read-across Augmentation | Pre-read-across implementation (preliminary) Mechanistic evidence evaluation (final) | Authoritative reviews and evidence maps Confidence in the biological framework^c^ Confidence in biological effects^c^ | Sufficiency and completeness of the understanding of the MoA or AOP supported by experimental evidence • Strength: number of key events and number of sources/targets tested for a key event • Consistency within a key event • Selectivity: discriminate between positive and negative
4. Chemistry similarity | Similarity justification | Read-across conduct | Read-across analyses Data matrix | Chemical structures available for the substances Structural and/or biological similarity between targets and sources (e.g., chemical structures, 2D-3D-parameters, and properties) are toxicologically or pharmacologically relevant to the endpoint
5. Toxicodynamic/ toxicokinetic similarity | Similarity justification | Read-across conduct | Read-across analyses Data matrix | Toxicodynamic and toxicokinetic (ADME) similarity (and not dissimilarity) are toxicologically or pharmacokinetically relevant to the endpoint. Metabolism data are available on one or more source chemicals
6. Concordance of the animal cancer data with intermediate effects and potency data (source chemicals) | Source chemicals Read-across Augmentation | Read-across conduct | Animal cancer assessment Read-across analyses output Data matrix including dose-response data | Consistency of cancer potency (if available) across source chemicals Dose-response and temporal relationship between relevant endpoints
7. Strength or robustness of the supporting data sets | Read-across Augmentation | Read-across conduct | Read-across analyses Data matrix Data gap filling | Consistency of the measurement or modeled data of the key events in the studies (in silico, in vitro, in chemico, nonstandard in vivo)

^a^ Factors are identified and modified from 12 factors in Table 3 (Schultz et al. 2019). Some factors were combined; documentation and context (which is the RoC purpose) is not included. We access the quality of the cancer evidence as part of the scoping activities, and this was moved up in the workflow.

^b^ Conclusions reached following the approach in the evaluation of Cancer Studies in Experimental Animals (Section 4).

^c^ Conclusions reached following the approach in the confidence judgment assessment for biological effects and pathway, Section 6.4.2 (Steps 1 and 2).

#### Step 2: Assess the Confidence for the Read-Across Prediction

Box 6-7 provides considerations for reaching a confidence judgment for read-across analyses. Assessing the strength (e.g., the similarity between target and source chemicals) of the cancer prediction for each target chemical or group of chemicals depends on the nature of the substance(s) under evaluation, and guidance is provided in the read-across plan.

Box 6-7 Confidence Judgments for Read-Across Predictions

Descriptor | Read-across Considerations
High | High in silico prediction (e.g., high-moderate correlation) AND Overall low uncertainty from the read-across analyses
Moderate | High in silico prediction AND Overall medium uncertainty from the read-across analyses
Inadequate | Low in silico prediction High in silico prediction AND Overall high uncertainty from the read-across analysis

In silico predictions can be generated through supervised (e.g., K-nearest neighbors, support vector machines) or unsupervised algorithms (e.g., clustering techniques). More specific statistical analysis will be provided in the provided in the protocol.

Overall uncertainty analysis is conducted for those target chemicals with high in silico predictions and determines the confidence judgment for the cancer prediction (e.g., low uncertainty translates to high confidence). Using weight-of-evidence and triangulation approaches, consideration of substance-specific issues, and scientific expert appraisal, we integrate the ratings across the uncertainty types (Step 1, Table 6-17) to reach an overall judgment. Minor uncertainty from all contributors is not required, and ratings for some factors may compensate for lower ratings for other factors. However, some types, such as the quality of cancer data for the sources or biological plausibility, are more relevant in the assessment. Indeed, to conduct a supervised read-across analysis, high confidence in the (1) category definition, (2) carcinogenicity of the source chemicals, and (3) biological plausibility of the read-across hypothesis is required.

Notably, these are considerations and not criteria for ratings and judgments and allow flexibility for expert opinion and substance-specific issues. Moreover, read-across methodologies are rapidly advancing, and this approach will adapt to include these innovations.

##### “Qualitative” clustering or read-across analyses

For some assessments, a “qualitative” (is the substance predicted to cause cancer) rather than a quantitative read-across and clustering analysis may be pursued. These analyses involve constructing data matrix tables of pertinent data, including trend analyses, and evaluating the uncertainty of the data, but do not calculate a statistical cancer prediction value (e.g., correlation). The uncertainty analyses are consistent with many of the factors identified for in silico models, such as confidence in the carcinogenicity of source chemicals, biological plausibility (e.g., MoA, toxicokinetics), and consistency of the biological effects and physical-chemical properties of the target chemicals within a category. However, as new read-across methods emerge, this approach may no longer be relevant.

##### Exemplar: Haloacetic acids found in disinfected drinking water

The NTP review of 13 HAAs applied a read-across data matrix table of physical and biochemical properties, biological effects (KCCs), and animal cancer data to assess data gaps and trends for possible listing of HAAs as a class, subclasses, or individual HAAs without human or animal cancer data (Atwood et al. 2019; NTP 2018b). Given low or inadequate confidence for the category that was due to inconsistency in the carcinogenicity or biological mechanisms for the source chemicals, no overall class, or subclasses (e.g., number and type of halogen) could be identified. However, using a read-across analogue approach based on the confidence of metabolism to a carcinogenic HAA and the strength of the mechanistic data, two additional haloacetic acids without animal or human carcinogenicity data were listed in the RoC. The analogue approach predicted specific cancer sites for the target based on the source chemicals.

#### Step 3: Assessing the Level of Evidence

The confidence judgment for read-across is integrated with all the relevant evidence to reach an LoE of carcinogenicity from mechanistic studies. A given evaluation may have several influential questions. For listing a substance as a reasonably anticipated carcinogen in the RoC, a public health congressionally mandated document, low uncertainty of the cancer prediction is required. The uncertainty assessment integrates the confidence of the MoA for the source chemicals and the biological effects of the target chemicals. Thus, high confidence for read-across translates to convincing LoE. However, evidence for biological effects not related to the MoA for a target chemical, depending on the adequacy of the database, may be integrated into the final assessment. As read-across predicts cancers for substances with little human and animal cancer data, moderate confidence does not translate into a listing recommendation (e.g., supporting LoE) but may identify research gaps.

Table 6-18 Step 3 Level of Evidence: Read-across Approaches

RoC Criterion | Convincing | Supporting
Q1 Plausibility: Predicted to cause cancer Q2: Member of a listed class | High confidence for read-across • Low uncertainty encompasses evaluation of MoA for the source chemicals and biological effect that are part of the evaluation for the target chemicals | Not relevant

## 6.6 Reporting

Information on reporting the cancer hazard evaluation is provided below, including methods to capture data extraction and study informativeness (Section 6.6.1), matrix table templates used in the read-across analysis (Section 6.6.2), and evidence-based tables for evaluating biological effects and read-across evidence (Section 6.6.3).

### 6.6.1 Data Extraction and Study Informativeness

Data extraction and study informativeness are captured in content management systems or software such as HAWC, Table Builder, Excel files, or Word tables. When relevant, findings may be visualized using software such as Tableau. The extent of the data extraction depends on how influential the studies are to the overall assessment (see Section 6.1, Fit-for-purpose).

### 6.6.2 Data Matrix

Table 6-19 Data Matrix Example for Read-across Analyses

Read-across Parameter | Chemical 1 | Chemical 2
Identifiers (e.g., ID, Nrs)
Chemical Structure
PC Property 1
PC Property 2
3D Parameter
TK 1: Metabolism
Biological Endpoint 1
In Vivo Carcinogenicity

### 6.6.3 Evidence-based Tables

#### Biological Effect Table

Examples of evidence-based tables for Steps 1 and 2 for evaluating biological effects:

Table 6-20 Step 1: Study Sets

Exposure | Endpoint | Evidence Type | Strength and Limitations | Assessment
Chemical X | Mutations | Exposed humans (nine studies) | Potential confounding | Consistent findings Some uncertainty
Chemical X | Mutations | Animal in vivo studies (five studies) | Acute exposure | Consistent findings Some uncertainty

Table 6-21 Step 2: Confidence Judgments

Influential Question | Outcomes | Study Sets | Assessment Summary and Rationale | Confidence Judgment
Strength of evidence for genotoxicity | Mutations Chromosomal damage | In vitro (human cells or mammalian cells) In vivo Exposed humans: mutation | Conclusion and uncertainty for each study set assessment Triangulation-like approach regarding biases across assessments. Informativeness of the KCC biomarkers | Moderate: exposed humans Note calls for individual biomarkers Note ex vivo or in vitro from human cells/tissues

#### Read-across Evidence

Examples of evidence-based tables for Steps 1 and 2 for evaluating read-across:

Table 6-22 Step 1: Uncertainty Analysis

Influential Question | Uncertainty | Evidence Type | Strengths and Limitations | Rating
Read-across Target 1 | Cancer data for source | Assessment and conclusions from animal cancer studies | Source chemicals are predicted to have sufficient evidence. | Minor uncertainty
Read-across Target 1 | Chemical similarly | Read-across analysis Data matrix | Similarities between chemicals are toxicologically relevant. | Minor uncertainty

Table 6-23 Step 2: Confidence for Read-across

Influential Question | Evidence | Assessment Summary and Rationale | Confidence Judgment
Read-across prediction: Target 1 | In silico prediction Uncertainty contributors | Conclusion for each uncertainty factor Weight of evidence/triangulation | Low uncertainty

## 6.7 New Directions

NAMs encompass a wide range of innovative techniques, including omics, imaging, in vitro assays, computational modeling, organ-on-a-chip platforms, high-throughput screening, and in silico approaches. Incorporating NAMs into the KCC framework represents a promising avenue for enhancing cancer hazard identification. These methodologies offer a deeper understanding of the intricate molecular mechanisms and pathway interactions involved in carcinogenesis, providing valuable supportive evidence within the KCC framework. In addition, when applied in the context of other evolving features of cancer, which include phenomena such as phenotypic plasticity, immune evasion, and polymorphic microbiomes, NAMs can provide insights into how chemicals influence these pathways, contribute to carcinogenesis, and elucidate their MoA or AOP. NAMs enable the investigation of complex interactions between chemicals and biological systems, including the tumor microenvironment and host immune response. By simulating these interactions in vitro or in silico, significant progress can be made in understanding how chemicals modulate the tumor microenvironment, promote neoangiogenesis and morphological changes, and evade immune surveillance, all of which are critical aspects of cancer development and progression. In the future, this ensures a comprehensive evaluation, that not only detects the early stages of carcinogenesis, but also acknowledges the acquisition of a complete malignant phenotype, providing a system toxicology-oriented and more holistic understanding of the carcinogenic potential of the tested chemicals. However, the successful integration of NAMs faces several challenges, notably the need to demonstrate the relevance, reliability, reproducibility, and predictive capability of NAMs. Achieving this goal would entail identifying pertinent studies that have effectively employed these methods, establishing standardized experimental protocols to ensure consistency, and validating the models to ensure the relevance, accuracy, and reliability of carcinogenic prediction and evaluations.

Furthermore, leveraging artificial intelligence (AI) techniques, such as machine learning and deep learning, within NAMs, enhances analyses of large datasets, discerns patterns, and predicts biological responses to chemical exposure more precisely, i.e., Read-Across Structure-Activity Relationship (RASAR) tool, thereby accelerating the identification of potential hazard (Luechtefeld et al. 2018). These advanced tools can offer valuable help in extrapolating quantitative dose-response relations, thereby strengthening the evidence base for predicting carcinogenicity and identifying mechanistic classes of agents already associated with cancer. Integration of multiple types of omic data from the same patient has been used in clinical research to characterize molecular and clinical features of cancers, which can inform treatment, monitor disease progression, and improve survival (Heo et al. 2021). Multiomic data capture biological responses or permutations caused by environmental or endogenous exposures and often refer to the genome, epigenome, transcriptome, proteome, and metabolome (Wu et al. 2023). Interest in integrating these data with exposure information to elucidate molecular mechanisms and pathways of human diseases (including cancer) is increasing. Omic data can capture multiple molecular mechanisms and represent (e.g., epigenetics) or measure KCCs or they might be molecular responses not fully captured by the 10 KCCs. Biological responses can be measured in samples from model systems (e.g., exposed animals or cells) or humans (epidemiological or clinical studies). New analytical technology in recent years, which can measure thousands of metabolites simultaneously, has advanced the utility of metabolomics in cancer research, including the creation of the Consortium of Metabolomics Studies. Studies (typically called metabolomic-wide association studies) have linked metabolites to exposure, cancer, and occasionally both. Although oncogenic metabolites (often endogenous) are associated to specific cancers and the hallmarks of cancer (Wishart 2022), we are not aware of any formal assessment of metabolomic data as a possible independent characteristic of carcinogens. Analogous to gene expression profiling, metabolites are often linked to biological pathways (Wieder et al. 2021), which may be related to the KCCs. Another growing advancement are microphysiological systems, which offer the potential to mimic tissue dynamics in vitro that could allow characterization of molecular pathway effects and their feed-forward progressions to toxicological phenotypes recognizable by pathologists.

Psychosocial stressors often share the same biological pathways; multiomics can help assess environmental exposure and psychosocial stressor interactions and shed light on contributors to health disparities and sensitive subpopulations. Identification of effect modifiers can help inform the interpretation of human cancer studies. Recent (2020 to 2023) publications on new methods for carcinogenic testing (e.g. Jacobs et al. 2020; NASEM 2023; Oku et al. 2022), and two workshops [Integrating Environmental Exposure Data with Other Omic Data for Cancer Epidemiology and Molecular Signatures of Exposure in Cancer (NIEHS 2023a; 2023b)] may help inform cancer hazard assessments and classifications.

This handbook will be updated as the scientific consensus on validation criteria is reached for using multiomics, NAMs, or AI in cancer hazard assessment advances.

## References

Atwood ST, Lunn RM, Garner SC, Jahnke GD. 2019. New perspectives for cancer hazard evaluation by the Report on Carcinogens: A case study using read-across methods in the evaluation of haloacetic acids found as water disinfection by-products. Environ Health Perspect. 127(12):125003. 10.1289/EHP5672 31854200
Ball N, Cronin MTD, Shen J, Blackburn K, Booth ED, Bouhifd M, Donley E, Egnash L, Hastings C, Juberg DR, et al. 2016. Toward Good Read-Across Practice (GRAP) guidance. ALTEX. 33(2):149–166. 10.14573/altex.1601251 26863606
Blackburn K, Stuard SB. 2014. A framework to facilitate consistent characterization of read across uncertainty. Regul Toxicol Pharmacol. 68(3):353–362. 10.1016/j.yrtph.2014.01.004 24457134
Chadeau-Hyam M, Athersuch TJ, Keun HC, De Iorio M, Ebbels TMD, Jenab M, Sacerdote C, Bruce SJ, Holmes E, Vineis P. 2011. Meeting-in-the-middle using metabolic profiling – A strategy for the identification of intermediate biomarkers in cohort studies. Biomarkers. 16(1):83–88. 10.3109/1354750X.2010.533285 21114379
European Chemicals Agency (ECHA). 2017. Read-Across Assessment Framework (RAAF). Helsinki, Finland: European Chemicals Agency. ECHA-17-R-01-EN. https://echa.europa.eu/documents/10162/17221/raaf_en.pdf
European Chemicals Agency (ECHA). 2023. Grouping of substances and read-across. Helsinki, Finland: European Chemicals Agency. [Accessed: February 14, 2023]. https://echa.europa.eu/support/registration/how-to-avoid-unnecessary-testing-on-animals/grouping-of-substances-and-read-across
Guyton KZ, Kyle AD, Aubrecht J, Cogliano VJ, Eastmond DA, Jackson M, Keshava N, Sandy MS, Sonawane B, Zhang L, et al. 2009. Improving prediction of chemical carcinogenicity by considering multiple mechanisms and applying toxicogenomic approaches. Mutat Res. 681(2-3):230–240. 10.1016/j.mrrev.2008.10.001 19010444
Guyton KZ, Rusyn I, Chiu WA, Corpet DE, van den Berg M, Ross MK, Christiani DC, Beland FA, Smith MT. 2018. Application of the key characteristics of carcinogens in cancer hazard identification. Carcinogenesis. 39(4):614–622. 10.1093/carcin/bgy031 29562322
Hanahan D. 2022. Hallmarks of cancer: New dimensions. Cancer Discov. 12(1):31–46. 10.1158/2159-8290.CD-21-1059 35022204
Hanahan D, Weinberg RA. 2011. Hallmarks of cancer: The next generation. Cell. 144(5):646–674. 10.1016/j.cell.2011.02.013 21376230
Heo YJ, Hwa C, Lee GH, Park JM, An JY. 2021. Integrative multi-omics approaches in cancer research: From biological networks to clinical subtypes. Mol Cells. 44(7):433–443. 10.14348/molcells.2021.0042 34238766
Howard BE, Phillips J, Miller K, Tandon A, Mav D, Shah MR, Holmgren S, Pelch KE, Walker V, Rooney AA, et al. 2016. SWIFT-Review: A text-mining workbench for systematic review. Syst Rev. 5:87. 10.1186/s13643-016-0263-z 27216467
International Agency for Research on Cancer (IARC). 1999. Species differences in thyroid, kidney and urinary bladder carcinogenesis. Capen CC, Dybing E, Rice JM, Wilbourn JD, editors. Lyon, France: International Agency for Research on Cancer. https://publications.iarc.fr/Book-And-Report-Series/Iarc-Scientific-Publications/Species-Differences-In-Thyroid-Kidney-And-Urinary-Bladder-Carcinogenesis-1999
International Agency for Research on Cancer (IARC). 2019. Preamble to the IARC monographs. Lyon, France: International Agency for Research on Cancer. https://monographs.iarc.who.int/iarc-monographs-preamble-preamble-to-the-iarc-monographs/
Jacobs MN, Colacci A, Corvi R, Vaccari M, Aguila MC, Corvaro M, Delrue N, Desaulniers D, Ertych N, Jacobs A, et al. 2020. Chemical carcinogen safety testing: OECD expert group international consensus on the development of an integrated approach for the testing and assessment of chemical non-genotoxic carcinogens. Arch Toxicol. 94(8):2899–2923. 10.1007/s00204-020-02784-5 32594184
Kienzler A, Barron MG, Belanger SE, Beasley A, Embry MR. 2017. Mode of action (MOA) assignment classifications for ecotoxicology: An evaluation of approaches. Environ Sci Technol. 51(17):10203–10211. 10.1021/acs.est.7b02337 28759717
Lester C, Byrd E, Shobair M, Yan G. 2023. Quantifying analogue suitability for SAR-based read-across toxicological assessment. Chem Res Toxicol. 36(2):230–242. 10.1021/acs.chemrestox.2c00311 36701522
Luechtefeld T, Marsh D, Rowlands C, Hartung T. 2018. Machine learning of toxicological big data enables read-across structure activity relationships (RASAR) outperforming animal test reproducibility. Toxicol Sci. 165(1):198–212. 10.1093/toxsci/kfy152 30007363
Lunn RM, Blask DE, Coogan AN, Figueiro MG, Gorman MR, Hall JE, Hansen J, Nelson RJ, Panda S, Smolensky MH, et al. 2017. Health consequences of electric lighting practices in the modern world: A report on the National Toxicology Program’s workshop on shift work at night, artificial light at night, and circadian disruption. Sci Total Environ. 607-608:1073–1084. 10.1016/j.scitotenv.2017.07.056 28724246
Lunn RM, Mehta SS, Jahnke GD, Wang A, Wolfe MS, Berridge BR. 2022. Cancer hazard evaluations for contemporary needs: Highlights from new National Toxicology Program evaluations and methodological advancements. J Natl Cancer Inst. 114(11):1441–1448. 10.1093/jnci/djac164 36029241
Moustakas H, Date MS, Kumar M, Schultz TW, Liebler DC, Penning TM, Salvito DT, Api AM. 2022. An end point-specific framework for read-across analog selection for human health effects. Chem Res Toxicol. 35(12):2324–2334. 10.1021/acs.chemrestox.2c00286 36458907
Myatt GJ, Ahlberg E, Akahori Y, Allen D, Amberg A, Anger LT, Aptula A, Auerbach S, Beilke L, Bellion P, et al. 2018. In silico toxicology protocols. Regul Toxicol Pharmacol. 96:1–17. 10.1016/j.yrtph.2018.04.014 29678766
National Academies of Sciences, Engineering, and Medicine (NASEM). 2023. Building confidence in new evidence streams for human health risk assessment: Lessons learned from laboratory mammalian toxicity tests. Washington, DC: National Academies Press. 10.17226/26906
National Center for Biotechnology Information (NCBI). 2023. Gene Expression Omnibus. Bethesda, MD: National Institutes of Health, National Library of Medicine, National Center for Biotechnology Information. [Accessed: February 14, 2023]. https://www.ncbi.nlm.nih.gov/geo/
National Institute of Environmental Health Sciences (NIEHS). 2023a. Integrating environmental data with other omics for cancer epidemiology, Tuesday & Wednesday, February 14 – 15, 2023. Research Triangle Park, NC: National Institutes of Health, National Institute of Environmental Health Sciences. [Last reviewed: May 3, 2023]. https://www.niehs.nih.gov/news/events/pastmtg/2023/environmental_data/index.cfm
National Institute of Environmental Health Sciences (NIEHS). 2023b. Molecular signatures of exposure in cancer: A joint NIEHS and NCI workshop, Thursday & Friday, June 29 – 30, 2023. Research Triangle Park, NC: National Institutes of Health, National Institute of Environmental Health Sciences. [Last reviewed: July 5, 2023]. https://www.niehs.nih.gov/news/events/pastmtg/2023/molecular-signatures/
National Toxicology Program (NTP). 2008. Report on Carcinogens background document for styrene. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. https://ntp.niehs.nih.gov/ntp/roc/twelfth/2010/finalbds/styrene_final_508.pdf
National Toxicology Program (NTP). 2013. Report on Carcinogens monograph on cumene. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. RoC Monograph 02. 10.22427/ROC-MGRAPH-02
National Toxicology Program (NTP). 2015. Report on Carcinogens monograph on trichloroethylene. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. RoC Monograph 05. 10.22427/ROC-MGRAPH-5
National Toxicology Program (NTP). 2018a. Report on Carcinogens monograph on antimony trioxide. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. RoC Monograph 13. 10.22427/ROC-MGRAPH-13
National Toxicology Program (NTP). 2018b. Report on Carcinogens monograph on haloacetic acids found as water disinfection by-products. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. RoC Monograph 12. 10.22427/ROC-MGRAPH-12
National Toxicology Program (NTP). 2021a. NTP cancer hazard assessment report on night shift work and light at night. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/NTP-CHR-NSWLAN
National Toxicology Program (NTP). 2021b. Substance profile: Benzidine and dyes metabolized to benzidine. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2021c. Substance profile: Cobalt. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2021d. Substance profile: Cumene. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2023. Adverse outcome pathways. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. [Last updated: March 29, 2023]. https://ntp.niehs.nih.gov/go/niceatm-aop
Oku Y, Madia F, Lau P, Paparella M, McGovern T, Luijten M, Jacobs MN. 2022. Analyses of transcriptomics cell signaling for pre-screening applications in the integrated approach for testing and assessment of non-genotoxic carcinogens. Int J Mol Sci. 23(21):12718. 10.3390/ijms232112718 36361516
Organisation for Economic Co-operation and Development (OECD). 2014. Guidance on grouping of chemicals, second edition. (OECD Series on Testing and Assessment, No. 194). Paris, France: OECD Publishing. 10.1787/9789264274679-en
Organisation for Economic Co-operation and Development (OECD). 2018a. Good cell culture practice (GCCP). In: Guidance Document on Good In Vitro Method Practices (GIVIMP). Paris, France: OECD Publishing. p. 161. 10.1787/9789264304796-16-en
Organisation for Economic Co-operation and Development (OECD). 2018b. Guidance document on Good In Vitro Method Practices (GIVIMP). (OECD Series on Testing and Assessment, No. 286). Paris, France: OECD Publishing. 10.1787/9789264304796-en
Organisation for Economic Co-operation and Development (OECD). 2023a. Grouping of chemicals: Chemical categories and read-across. Paris, France: Organisation for Economic Co-operation and Development. [Accessed: February 21, 2023]. https://www.oecd.org/chemicalsafety/risk-assessment/groupingofchemicalschemicalcategoriesandread-across.htm
Organisation for Economic Co-operation and Development (OECD). 2023b. [Homepage]. Paris, France: Organisation for Economic Co-operation and Development. [Accessed: February 22, 2023]. https://www.oecd.org/
Pamies D, Leist M, Coecke S, Bowe G, Allen DG, Gstraunthaler G, Bal-Price A, Pistollato F, de Vries RBM, Hogberg HT, et al. 2022. Guidance document on Good Cell and Tissue Culture Practice 2.0 (GCCP 2.0). ALTEX. 39(1):30–70. 34882777
Patlewicz G, Ball N, Boogaard PJ, Becker RA, Hubesch B. 2015. Building scientific confidence in the development and evaluation of read-across. Regul Toxicol Pharmacol. 72(1):117–133. 10.1016/j.yrtph.2015.03.015 25857293
Patlewicz G, Cronin MTD, Helman G, Lambert JC, Lizarraga LE, Shah I. 2018. Navigating through the minefield of read-across frameworks: A commentary perspective. Comput Toxicol. 6:39–54. 10.1016/j.comtox.2018.04.002
Patlewicz G, Helman G, Prachi P, Shah I. 2017. Navigating through the minefield of read-across tools: A review of in silico tools for grouping. Comput Toxicol. 3:1–18. 10.1016/j.comtox.2017.05.003 30221211
Pestana C, Enoch SJ, Firman JW, Madden JC, Spînu N, Cronin MTD. 2022. A strategy to define applicability domains for read-across. Comput Toxicol. 22:100220. 10.1016/j.comtox.2022.100220
Rowan A, Spielmann H. 2019. The current situation and prospects for tomorrow: Toward the achievement of historical ambitions. In: Balls M, Combes R, Worth A, editors. The History of Alternative Test Methods in Toxicology. London, UK: Academic Press. p. 325-331. 10.1016/B978-0-12-813697-3.00035-4
Samet JM, Chiu WA, Cogliano V, Jinot J, Kriebel D, Lunn RM, Beland FA, Bero L, Browne P, Fritschi L, et al. 2020. The IARC monographs: Updated procedures for modern and transparent evidence synthesis in cancer hazard identification. J Natl Cancer Inst. 112(1):30–37. 10.1093/jnci/djz169 31498409
Savitz DA, Wellenius GA, Trikalinos TA. 2019. The problem with mechanistic risk of bias assessments in evidence synthesis of observational studies and a practical alternative: Assessing the impact of specific sources of potential bias. Am J Epidemiol. 188(9):1581–1585. 10.1093/aje/kwz131 31145434
Schultz TW, Amcoff P, Berggren E, Gautier F, Klaric M, Knight DJ, Mahony C, Schwarz M, White A, Cronin MTD. 2015. A strategy for structuring and reporting a read-across prediction of toxicity. Regul Toxicol Pharmacol. 72(3):586–601. 10.1016/j.yrtph.2015.05.016 26003513
Schultz TW, Richarz AN, Cronin MTD. 2019. Assessing uncertainty in read-across: Questions to evaluate toxicity predictions based on knowledge gained from case studies. Comput Toxicol. 9:1–11. 10.1016/j.comtox.2018.10.003
Smith MT, Guyton KZ, Gibbons CF, Fritz JM, Portier CJ, Rusyn I, DeMarini DM, Caldwell JC, Kavlock RJ, Lambert PF, et al. 2016. Key characteristics of carcinogens as a basis for organizing data on mechanisms of carcinogenesis. Environ Health Perspect. 124(6):713–721. 10.1289/ehp.1509912 26600562
Smith MT, Guyton KZ, Kleinstreuer N, Borrel A, Cardenas A, Chiu WA, Felsher DW, Gibbons CF, Goodson WH 3rd, Houck KA, et al. 2020. The key characteristics of carcinogens: Relationship to the hallmarks of cancer, relevant biomarkers, and assays to measure them. Cancer Epidemiol Biomarkers Prev. 29(10):1887–1903. 10.1158/1055-9965.EPI-19-1346 32152214
Sozanska AM, Fletcher C, Bihary D, Samarajiwa SA. 2020. SpiderSeqR: An R package for crawling the web of high-throughput multi-omic data repositories for data-sets and annotation. bioRxiv. 10.1101/2020.04.13.039420
Tice RR, Bassan A, Amberg A, Anger LT, Beal MA, Bellion P, Benigni R, Birmingham J, Brigo A, Bringezu F, et al. 2021. In silico approaches in carcinogenicity hazard assessment: Current status and future needs. Comput Toxicol. 20:100191. 10.1016/j.comtox.2021.100191 35368437
U.S. Environmental Protection Agency (USEPA). 2018. Application of systematic review in TSCA risk evaluations. Washington, DC: U.S. Environmental Protection Agency, Office of Chemical Safety and Pollution Prevention. EPA Document No. 740-P1-8001. https://www.epa.gov/sites/default/files/2018-06/documents/final_application_of_sr_in_tsca_05-31-18.pdf
Walker VR, Schmitt CP, Wolfe MS, Nowak AJ, Kulesza K, Williams AR, Shin R, Cohen J, Burch D, Stout MD, et al. 2022. Evaluation of a semi-automated data extraction tool for public health literature-based reviews: Dextr. Environ Int. 159:107025. 10.1016/j.envint.2021.107025 34920276
Wang Z, Walker GW, Muir DCG, Nagatani-Yoshida K. 2020. Toward a global understanding of chemical pollution: A first comprehensive analysis of national and regional chemical inventories. Environ Sci Technol. 54(5):2575–2584. 10.1021/acs.est.9b06379 31968937
Wieder C, Frainay C, Poupin N, Rodríguez-Mier P, Vinson F, Cooke J, Lai RP, Bundy JG, Jourdan F, Ebbels T. 2021. Pathway analysis in metabolomics: Recommendations for the use of over-representation analysis. PLOS Comput Biol. 17(9):e1009105. 10.1371/journal.pcbi.1009105 34492007
Wishart D. 2022. Metabolomics and the multi-omics view of cancer. Metabolites. 12(2):154. 10.3390/metabo12020154 35208228
Wu H, Eckhardt CM, Baccarelli AA. 2023. Molecular mechanisms of environmental exposures and human disease. Nat Rev Genet. 24(5):332–344. 10.1038/s41576-022-00569-3 36717624