# 5 Evaluation of Disposition and Toxicokinetic Data

## Introduction and Objective

This section describes the approach used to review disposition or ADME (absorption, distribution, metabolism, and excretion) and toxicokinetics (rate and extent of those processes) of the substance(s) under review.

The Report on Carcinogens (RoC) listing criteria note that cancer hazard conclusions (e.g., a listing recommendation for known or reasonably anticipated to be a human carcinogen) are based on scientific judgment, with consideration given to all relevant information. Relevant information can include metabolism, toxicokinetics, and other ADME data (Slitt 2019). ADME and toxicokinetic (defined now as ADME) data can impact the listing directly or indirectly. For example, some listed chemical classes are based on metabolism to a known or reasonably anticipated carcinogen. ADME can inform the interpretation of all components of the cancer hazard evaluation, such as the quality of exposure biomarkers used in biomonitoring and human cancer epidemiology studies, human relevance of animal cancer studies, and mechanisms of action. It is important to assess the likely effect of ADME and toxicokinetic data as early as possible in the overall evidence evaluation process.

### Primary Objectives

- To determine whether ADME evidence is influential for reaching a listing recommendation, and if so, to assess this evidence
- To discuss how ADME informs the mechanism of action and biological plausibility or read-across approaches

### Secondary Objectives

- Discuss how the substance is absorbed, distributed, metabolized, and excreted in humans and experimental animals
  - Assess whether ADME data help explain target cancer sites
- Identify the metabolites of the substance and what metabolites are considered in the carcinogenicity assessment
  - Identify the ultimate carcinogenic form—parent compound or metabolite(s)
- Discuss any interspecies differences/similarities in ADME. For example, are they qualitative or quantitative, and could they affect the interpretation of the relevance of animal data to humans?

### Components of the Evaluation of ADME and Toxicokinetic Data

- Develop the framework.
  - Develop a literature search strategy, conduct the literature search, and screen, tag, and map the studies.
  - Develop approach and protocol.
- Extract data and evaluate the quality of the selected studies.
- Review and integrate the evidence across studies.

## 5.1 Evaluation Framework Development

The evaluation of ADME data differs from the human and animal cancer sections of cancer hazard evaluations as it often relies on data from authoritative or other contemporary reviews supplemented by relevant primary studies. The fit-for-purpose scoping activities are stepwise and iterative to determine the extent and depth of ADME knowledge, identify the importance of ADME in the cancer hazard evaluation and listing decisions (e.g., influential questions) and determine the most appropriate approach for reviewing the available literature.

First, the evaluation team searches authoritative sources and citation databases for reviews (see below for methods) on ADME information to determine the relative impact and importance of ADME and toxicokinetic data on reaching hazard identification conclusions (see Box 5-1 for guidance). These reviews also inform whether there are any issues or concerns in the ADME data that would warrant a deeper dive into the literature (e.g., interspecies differences in ADME). Reviews are assessed for their quality for inclusion, detail of reporting, and recency of reviewed studies. Primary studies cited in the reviews may be retrieved to ensure accurate reporting by the reviews.

Box 5-1 Guiding Questions to Inform Evaluation Approach

Is an adequate—recent, sufficiently detailed—authoritative review available?

How critical are the data to the overall cancer hazard listing recommendation?

- Does ADME directly affect the listing conclusion?
- What is the extent that ADME contribute to the cancer mechanisms or interpretation of the cancer studies in experimental animals?
- Is any issue for ADME likely to be an influential mechanistic question?
- What evidence types (human, animal, in vitro) are available and is there evidence of inter-species differences?

If no recent reviews of adequate quality are available, the evaluation team will search the literature for primary studies to identify critical scientific issues and influential questions. Using these scoping and literature searches, the team will determine the adequacy of the review for addressing these issues and what targeted searches are needed. Primary studies cited in the reviews may also be retrieved. The scoping activities also help focus the framework [EECO] used for searching and selecting the literature. (EECO = evidence type [e.g., humans, animals, in vitro], comparison group and outcome or endpoint), and the source (review vs. primary studies) for the EECO. On rare occasions, an RoC monograph may summarize ADME only from authoritative reviews (such as IARC, which undergo quality checks and peer review).

### 5.1.1 Literature Search Methods

Searches are conducted in PubMed and in at least one other database (such as Scopus or Web of Science), depending on the substance, using the concepts in Table 5-1 below (using the Boolean operator “OR”) in conjunction with terms for the substances or their metabolites (using the Boolean operator “AND”). (See the Handbook appendix (https://ntp.niehs.nih.gov/whatwestudy/assessments/cancer/handbook/index.html) on the NTP website for the ADME search strings.)

Citations retrieved from literature searches are uploaded to a web-based systematic review software application (such as Health Assessment Workspace Collaborative [HAWC]) and screened by reviewers using predefined inclusion/exclusion criteria. Studies are initially included in the evaluation if they report ADME or toxicokinetic data in humans or experimental animals for the substance under review, or in a relevant in vitro system for the substance under review.

Studies meeting the inclusion criteria can be mapped by publication type (primary versus secondary), species or sex, route of exposure, specific ADME topic(s), and type of study (in vivo versus in vitro). Primary studies will be included in the assessment to supplement gaps in reviews.

Table 5-1 Examples of Concepts Used in Searches for ADME Studies

PubMed, Scopus, and Web of Science | MeSH Terms Used in PubMed
ADME Bioavailability Tissue-distribution Bioconcentration Metabolite Excretion Elimination Metabolism polymorphism Toxicokinetics | Toxicokinetics Pharmacokinetics Metabolism Activation Metabolic Cytochrome P-450 enzyme system

Note that these are examples of search terms and not the detailed or fully developed search string used in the actual literature search.

### 5.1.2 Protocol

The protocol (part of the overall monograph protocol) contains the following sections: (1) framework development, which provides information on literature searches and mapping, influential and other key questions, and (2) the approach, and guidance (if relevant) on assessing study informativeness and reaching conclusions about any influential questions.

## 5.2 Study Informativeness Assessment

The assessment of study informativeness (e.g., bias analysis and study sensitivity) follows a fit-for-purpose approach and is consistent with the strategy for assessing mechanistic studies (see Section 6.3). The evaluation of study informativeness of primary studies depends on how impactful the literature is for answering questions that may influence the overall cancer hazard classification. ADME studies vary widely in study design and detail, and specific bias questions are not part of our handbook; however, study informativeness considerations for mechanistic studies (see Section 6.3) may also be relevant to the ADME studies. Other sources for evaluating the strengths and weaknesses in the studies include Good Laboratory Practices, OCED guidelines, scientific judgment, and consultation with technical advisors (OECD 2010). ADME data used for RoC cancer hazard evaluations are often from authoritative reviews; study informativeness assessment of individual studies in these reviews is usually not conducted unless needed to inform the ADME assessment such as when the studies report conflicting results. For example, the quality of analytical methods used to measure metabolites or physiologically based pharmacokinetic (PBPK) models may explain potential discrepancies between studies (Barton et al. 2007).

## 5.3 Evidence Integration Across Studies

For most evaluations, the monograph provides a narrative summary and relevant tables of ADME data in exposed humans and animals, and in vitro (see Section 5.4 for examples of ADME data). For substances with influential questions, we assess the evidence for its informativeness, (see Section 5.2) and consistency to reach conclusions regarding each question and scientific issues (see Box 5-2).

Box 5-2 Guiding Questions to Inform Evaluation Approach

Identification of bioactive and carcinogenic metabolites

Extent and nature (e.g., species) of the metabolism (conclusion)

Biological plausibility (conclusion)

Other potential effects of ADME on mechanistic events, e.g., enterohepatic circulation

Biological plausibility encompasses consideration of species similarities and differences and effects of dose level and exposure routes on ADME and observed tumor sites. Studies in human-relevant (humans or human tissues and cells) and biologically relevant (in vivo studies) are considered the most informative, but data from all evidence types can be integrated into the ADME assessment. Data from exposed humans are the most relevant but are usually sparse, and many studies are limited as they measure ADME in only a few volunteers. In addition, these data may not reflect enzyme polymorphisms or other effect modifiers within a larger and more diverse population. Often metabolism studies using human cell lines or tissues help to fill this data gap, support findings from in vivo studies, and provide a valuable link in describing similarities and differences between humans and in vivo or in vitro experimental animal data, or both. Qualitative human cancer hazard assessments consider all pharmacokinetic data, including in vitro information using cells or tissue models from humans and experimental animals. Often human data are not available and integration of the body of evidence considers species differences and/or similarities to human physiology. Conclusions regarding influential questions and other ADME evidence may be integrated with evidence from other data streams and the overall cancer hazard assessment (see Table 5-2 for examples).

Table 5-2 ADME Examples from Report on Carcinogens Evaluations

Example | Evidence Stream | Issue
Antimony trioxide | Animal cancer studies | Particle overload: Antimony trioxide lung concentrations in control and tumor tissue by dose level. Lung tumors in rodents occurred at doses in which lung clearance overload did not occur and were attributed to antimony trioxide toxicity and not inert particles (NTP 2021a).
Trichlorethylene^a^ | Mechanistic data | Mechanism: Glutathione conjugation (GSH) pathway results in metabolic and cytotoxic metabolites in the kidneys. This mechanism is considered for trichloroethylene-induced kidney tumors in humans and experimental animals (NTP 2021c).
Diazoaminobenzene^a^ | Overall evaluation | Metabolism: Diazoaminobenzene was listed based on metabolism to benzene. The ADME section provided information on the nature and extent of metabolism to benzene (e.g., the metabolic pathway of diazoaminobenzene is similar to benzene and metabolism is quantitative) (NTP 2021b).

^a^ See Section 7.

## 5.4 Reporting

As mentioned above, this section summarizes ADME information from authoritative and/or other contemporary reviews supplemented by key studies. The ADME section is organized into subsections that address the main topics (i.e., absorption, distribution, metabolism, and excretion) or various combinations of these topics. Toxicokinetic data may be presented as a separate subsection or included within the other subsections. If metabolism is a key step in carcinogen formation for read-across methods, a comparison of ADME data for source chemicals to the target chemicals is reported (see Table 5-2).

### 5.4.1 Data Extraction for Selected Studies

Examples of relevant ADME and toxicokinetic data that may be extracted for the four primary topics are listed in Table 5-3; however, these lists should neither be considered exhaustive nor are they necessarily required elements in all cancer hazard assessments (Krishnan 2019). Data extraction is conducted on a case-by-case basis and may include a narrative summary, Word tables, or web applications such as Table Builder or HAWC. Each substance or substances considered in an RoC monograph will present different challenges depending, in part, on the availability of data to address the key questions listed above.

Table 5-3 Examples of ADME and Toxicokinetic Data

Topic | Types of Data (Human and Animal) | Relevant Toxicokinetic Parameters | Tables and Figures
Absorption | Data for all relevant routes (e.g., oral, inhalation, dermal) • Bioavailability • Permeability coefficients • Low-dose vs. high-dose comparisons • Other factors that affect absorption • Particle deposition in airways | C_max_ T_max_ | Optional As needed
Distribution | General description (e.g., rapid and uniform) • Serum/plasma protein binding • Tissue burdens/storage tissues • Active/passive transport into tissues/cells • Route of exposure comparisons | Vd Blood concentration-time profiles AUC T_½_ Partition coefficients: blood:tissue blood:plasma blood:air | Optional As needed
Metabolism | Metabolites • Metabolizing enzymes and tissues • Route of exposure/dose effects • Induction/inhibition • Interspecies comparisons • Age/gender differences • Polymorphisms (fast/slow metabolizer) • First pass • Saturation • Glutathione depletion | V_max_ K_m_ Note: PBPK models, if available, can provide information on relative importance of competing metabolic pathways | Required Figure(s) showing metabolism of the substance(s) including all known pathways, metabolites, and enzymes Optional Other tables/figures as needed
Excretion | Data for all relevant routes (e.g., urinary, biliary, fecal, exhalation, sweat) • Enterohepatic circulation • Parent vs. metabolites • Mechanisms (active or passive) • Renal tubular secretion and reabsorption • Glomerular filtration rate | Cl (total, renal, nonrenal) T_½_ | Optional As needed

AUC = area under the curve; Cl = clearance; C_max_ = peak or maximum blood concentration; K_m_ = Michaelis-Menton constant (chemical concentration at one-half the maximum reaction rate); PBPK = physiologically based pharmacokinetic model; T_½_ = half-life; T_max_ = time to maximum blood concentration; Vd = apparent volume of distribution; V_max_ = maximum reaction rate.

## References

Barton HA, Chiu WA, Setzer RW, Andersen ME, Bailer AJ, Bois FY, DeWoskin RS, Hays S, Johanson G, Jones N, et al. 2007. Characterizing uncertainty and variability in physiologically based pharmacokinetic models: State of the science and needs for research and implementation. Toxicol Sci. 99(2):395–402. 10.1093/toxsci/kfm100 17483121
Krishnan K. 2019. Chapter 7: Toxicokinetics. In: Klaassen CD, editor. Casarett & Doull’s Toxicology: The Basic Science of Poisons. 9th ed. New York, NY: McGraw-Hill Education. https://accesspharmacy.mhmedical.com/content.aspx?bookid=2462&sectionid=202672178
National Toxicology Program (NTP). 2021a. Substance profile: Antimony trioxide. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2021b. Substance profile: Diazoaminobenzene. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2021c. Substance profile: Trichloroethylene. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
Organisation for Economic Co-operation and Development (OECD). 2010. Test no. 417: Toxicokinetics. (OECD Guidelines for the Testing of Chemicals, Section 4). Paris, France: OECD Publishing. 10.1787/9789264070882-en
Slitt AL. 2019. Chapter 5: Absorption, distribution, and excretion of toxicants. In: Klaassen CD, editor. Casarett & Doull’s Toxicology: The Basic Science of Poisons. 9th ed. New York, NY: McGraw-Hill Education. https://accesspharmacy.mhmedical.com/content.aspx?bookid=2462&sectionid=194919337