# 4 Evaluation of Cancer Studies in Experimental Animals

## Summary

The overall cancer hazard evaluation consists of several steps: (1) scoping and mapping the literature to determine the evaluation framework and protocol development, (2) evaluating study informativeness, (3) interpreting the studies and integrating the evidence across studies, and (4) applying the Report on Carcinogens (RoC) listing criteria to reach a conclusion about the level of evidence for carcinogenicity from studies in experimental animals. The study informativeness assessment questions relate to the potential for bias (internal validity) and to study sensitivity, which is the study’s ability to detect a true effect. The overall assessment integrates the responses to the questions across domains (e.g., study design, exposure conditions). This integration allows for an overall study interpretation, which considers the findings and the potential for bias. Evidence integration considers relevance to humans (external validity), conclusions about exposure-related effects for observed cancerous tumors, and the level of evidence for a specific type of cancer across studies. The RoC listing criteria for sufficiency of evidence for a cancer outcome is applied to these results.

## Introduction and Objective

This section describes the systematic review and evidence integration methods for assessing the level of evidence for the carcinogenicity of a substance (agent, substance, mixture, or exposure circumstance or scenario) from experimental animal studies. Although this section focuses on cancer studies, the study informativeness evaluation questions and guidelines also apply to experimental studies on cancer mechanisms (Section 6 describes the methods for evaluating mechanistic data).

This handbook describes general methods common to all evaluations. In addition, specific protocols will be developed that adapt these methods, identify scientific issues, and develop considerations specifically for each substance. The methods have been updated from the 2015 edition of the handbook; the original methods were informed by input from NTP/NIEHS toxicologists.

The key scientific questions and the major steps in the cancer hazard evaluation are listed below. Subsequent sections provide detailed methods for conducting the evaluation.

### Key Questions for Cancer Hazard Evaluations

#### Primary Question

- What is the level of evidence (i.e., sufficient or not sufficient) for the carcinogenicity of the substance from studies in experimental animals? (See Section 4.3.)

#### Secondary Questions

- Which experimental animal cancer studies should be included in the review?
- What are key issues for evaluation of the studies?
- What are the methodological strengths and limitations of these studies?
- What are the target tissue sites?
- Are there external validity concerns about the route of administration, human-relevant mechanism of action or other reasons?

### Process and Components of the Cancer Hazard Assessment

- Develop the cancer hazard framework for experimental animal studies (Section 4.1).
  - Develop the literature search strategy: search, identify, select, and map literature based on the initial Model, Exposure, Comparison group, and Outcome (MECO) statement and scoping activities.
  - Develop the protocol.
- Evaluate the informativeness of the experimental animal studies (Section 4.2).
- Integrate the evidence and reach health hazard conclusions from the animal cancer studies (Section 4.3).

Figure 4-1

Components of the Assessment of Animal Cancer Studies for the Cancer Hazard Evaluation

The first step in the evaluation is to develop a framework for the review. This involves scoping and mapping the literature. Studies are included based on the MECO statement. Next, through a structured approach using questions and guidelines, the included studies are evaluated for their ability to inform the cancer evaluation based on the bias assessment (internal validity) and study sensitivity (ability to detect a true effect). The last step involves evaluating the individual studies and integrating the evidence across studies. Evidence integration considers relevance to humans (external validity), conclusions about exposure-related effects for observed cancerous tumors, and the level of evidence for a specific type of cancer across studies.

## 4.1 Cancer Hazard Framework Development

Conducting a cancer hazard assessment for a substance begins with scoping and problem formulation activities to develop the research questions and MECO statement (similar to PECO, with “population” replaced by animal “model”), literature search strategies, and protocol for the health hazard evaluation of a specific exposure. Whereas Section 1 discusses scoping and problem formulation activities for the overall cancer hazard evaluation, this section focuses on methods related specifically to the review of experimental animal studies. The process is necessarily iterative (i.e., there may be several cycles of literature searches and evidence mapping).

### 4.1.1 Literature Search Strategy, Study Selection, and Evidence Mapping

The cancer evaluation component of the draft monograph evaluates all the relevant cancer studies in experimental animals that have been exposed to a specific substance. As per the RoC process, studies must be peer reviewed and publicly available. Primary studies included in review articles (such as authoritative sources) may be included if there is adequate information to evaluate them. The general approach to identifying and selecting relevant literature is discussed in the search string document (https://ntp.niehs.nih.gov/whatwestudy/assessments/cancer/handbook/index.html); this section discusses the literature search strategy, inclusion/exclusion criteria, and evidence-mapping procedures that are specific to cancer studies in experimental animals.

Searches are conducted in PubMed and at least one other bibliographic database (such as Scopus or Web of Science) using search terms for the substance combined with search terms related to cancer and experimental animal studies. (See Figure 4-1 for examples of search concepts.) Search terms for the substance may be chemical synonyms, which usually are identified from National Library of Medicine databases (e.g., ChemIDplus, PubChem). Relevant literature is also identified from authoritative reviews (e.g., IARC monographs), government websites (e.g., PubChem, CompTox Chemicals Dashboard), other databases (see Appendix B), and citations in retrieved studies. Searches specific for the substance will be developed in the protocol for that substance.

Table 4-1 Examples of Concepts Used in Searches for Cancer Studies in Experimental Animals

PubMed, Scopus, and Web of Science | | MeSH Terms Used in PubMed
Animal Terms | Cancer Terms | Animal Terms | Cancer Terms
Animal Mouse Mice Rats Hamsters “Guinea pig” | Cancer Neoplasm Carcinogens Malignancy Oncogene Tumor | Models, animal Animal Experimentation Animal, laboratory | Neoplasms Carcinogens

Citations retrieved from literature searches are uploaded to web-based systematic review software, such as Health Assessment Workspace Collaborative (HAWC), and screened by two reviewers using predefined inclusion/exclusion criteria (Box 4-1). Studies meeting these criteria often include traditional cancer bioassays and studies in genetically modified animals that are prone to cancer development (e.g., Tp53 mouse, RasH2 mouse). In addition, subchronic toxicity studies may be included if there is evidence of cancer or of lesions considered part of a morphologic continuum to neoplasia. In general, subchronic or chronic toxicology (conducted in traditional animal models) studies with durations of less than one year (for rats and mice) with no neoplastic outcomes are excluded from further consideration unless they are in sensitive models (e.g., newborn animals). Studies with no concurrent control group may be excluded from further consideration on a case-by-case basis.

Box 4-1 Selection Criteria for Animal Cancer Studies

Studies are initially included if they meet the MECO:

- Model: Conducted in a relevant animal model
- Exposure: Test the appropriate exposures
- Comparison group: Have appropriate controls (unexposed)
- Outcome: Measure neoplastic endpoints

Supporting studies

- Have non-cancer data that is informative for a cancer assessment, such as reporting preneoplastic lesions
- Describe non-neoplastic lesions that are considered part of a morphologic continuum to neoplasia

Studies meeting the inclusion criteria can be tagged (supplemented by limited data extraction) according to cancer type, species, exposure route, study design, or other relevant issues. These tags (or data extraction) can be used to create interactive systematic evidence map visualizations of the available animal cancer data using visualization programs such as Tableau. Evidence maps inform or refine the MECO statement, protocol, and reporting of the studies. Final selection of studies for inclusion is based on the refined MECO statement.

### 4.1.2 Protocol Development

The protocol for each substance assessment includes a section for the systematic review of animal cancer studies. It consists of the following sections: (1) developing the framework, which provides information on the objectives, identifying and mapping the evidence, the MECO statement, and substance-specific scientific issues, (2) detailed methods for evaluating study informativeness, such as the potential for exposure and outcome misclassification, confounding, and other potential biases that may be important in evaluating the findings for the hazard evaluation and (3) methods for evaluating and integrating the evidence across studies. Information on data extraction and roles of the evaluation team may also be included. Therefore, protocol development requires background research on the substance and its properties, a basic understanding of the types of studies available, and identification of the key issues and questions to be addressed. A protocol is written after an initial review and selection of the literature.

## 4.2 Study Informativeness Assessment

This section describes the assessment of the informativeness of the individual studies, including the steps in the process; the responses for each step; signaling questions to evaluate study informativeness, including internal validity (i.e., biases) and study sensitivity; and the overall study judgment to inform the cancer hazard evaluation. Study evaluations are reported in tabular and text format (see Section 4.4).

### 4.2.1 Domain-based Approach

Each primary study is systematically evaluated for its informativeness by two independent reviewers using a series of signaling questions related to the following study performance domains: study design, exposure conditions, outcome assessment, potential confounding, and analysis. Questions about sensitivity and biases apply to both study design and exposure conditions. Guidance for answering the signaling questions is discussed in Section 4.2.2. These questions highlight concerns toxicologists usually consider when evaluating study informativeness; they are used to increase transparency but are not meant to be a checklist.

Box 4-2 Bias Concern Judgements

No or minimal concern: The study design or methodologies are ideal or very close to the ideal study characteristics, and potential bias is unlikely or minor. These studies generally are considered informative for the cancer hazard evaluation.

Some concern: The study design or methodologies indicate a possible low-to-moderate concern for bias. These studies generally are considered informative for the cancer hazard evaluation.

Moderate or major concern: The study design or methodologies suggest a large potential for a specific type of bias. Depending on the direction and distortion of the potential bias, the study still may be informative for cancer hazard evaluation but should be viewed with caution.

Critical concern: The distortion resulting from bias likely makes the study findings unreliable for cancer hazard identification. In most cases, concerns for study sensitivity (unless severe) would not result in excluding the study from the assessment. This category is rare.

Direction of bias:

- ↑Away from the null, or overestimation of the effect.
- ↓Toward the null, or underestimation of the effect.
- Not known (unable to determine).

Magnitude of bias: Minimal, moderate or major, or unknown. In most cases, the magnitude will be unknown or subjective, but, where available, it will be based on the analysis.

The potential for a given bias in a study does not necessarily or automatically mean that the findings of the study should be disregarded. When adequate information is available, the direction of the bias (away or toward the null) and magnitude of the bias should be considered. For example, if the administered substance contained carcinogenic impurities, the degree of the tumor response attributed to the impurity could be calculated (e.g., based on the percent and potency of the impurity). In evaluating whether there is a potential bias or limitation, reviewers provide their judgments by comparing the study elements with those of an ideal study for a specific end point (see Box 4-2 for bias concern judgments). Ideal study elements pose low-to-minimal concern about potential bias and provide sufficient sensitivity to detect an effect if present. In some cases, a judgment may not be possible, because of the complexity of the issues, and the study informativeness evaluation will be discussed in narrative text.

Differences in reviewer rankings are resolved through mutual discussion with reference to the original data source. A small subset of studies may be used in a “pilot” phase, so that any ambiguity can be discussed and resolved before evaluation of the full set of studies proceeds. If the information needed to evaluate a signaling question is inadequate, the study authors may be contacted.

### 4.2.2 Study Informativeness Evaluation Questions and Guidance

The study evaluation is used to assess the informativeness of the studies and to inform the interpretation of the study findings (see Section 4.2.2). Signaling questions (e.g., questions to aid the reviewer in the bias evaluation) and considerations for each of the different types of bias and for sensitivity are listed below. Some study elements may overlap between different domains. Study assessments may indicate that a study should not be carried forward to the cancer hazard evaluation, or they may be used to indicate, across the body of evidence, which findings are more informative than others in the hazard evaluation.

#### Study Design

The study design domain evaluates two questions on biases in the study and one question on the study’s sensitivity (Table 4-2). Bias assessment includes questions on randomization and controls. Concurrent controls are the most relevant comparison group for evaluating potential exposure-related tumor effects. Evaluation of study sensitivity integrates study model, statistical power, and study duration.

Table 4-2 Study Design: Questions and Responses

Signaling Questions^a^ | Guidance | Response Options^b^
Bias Questions
Randomization
Is there concern that the methods by which animals were randomized to groups were inadequate? | Ideally, the randomization method was reported and was based on ensuring that all animals had an equal probability of being assigned to any given control or experimental group. | No or minor concern Animals were adequately randomized to control and experimental groups. Critical concern There is evidence that animals were not randomized to control and experimental groups and there is convincing evidence that this biases the findings.
Controls
Is there concern that the concurrent control group was not adequate for evaluating effects across treatment groups? • If no concurrent controls were used, were historical controls reported that could be used in place of concurrent controls? | Concurrent controls are considered to be the most relevant comparison group for evaluating potential exposure-related tumor effects. Ideally, the concurrent control group included at least as many animals as did each treatment group. The absence of an appropriate control group, by itself, may be sufficient for judging a study inadequate for the cancer hazard evaluation. However, in some cases, historical controls of the same animal strain/stock and from the same laboratory may serve in place of concurrent controls. The experimental design of some studies evaluating co-carcinogens may not include untreated (or vehicle) concurrent controls, but generally include single-carcinogen or positive controls, which can result in acceptable study quality. | No or minor concern Controls were treated as similarly as possible to the exposed animals but without exposure to the test substance (e.g., appropriate vehicle controls were used). Critical concern No concurrent or relevant historical controls (that could be used in place of concurrent controls) were available.
Sensitivity Question
Is there concern that the study design (i.e., animal model, number of animals/dose group and control group, and study duration) was sensitive enough to adequately detect a neoplastic effect if present? This question considers these factors: • Animal model • Statistical power (number of animals/group) • Study duration | The sensitivity rating integrates the animal model, statistical power, and study design. In some cases, one factor may compensate for limitations in another factor (e.g., a short study duration may be compensated for by a highly sensitive animal model that develops tumors within that duration). The study should use an animal model that is sensitive for detecting tumors (e.g., the background tumor rates for the tumor type are known, and the animal is sensitive to effects via the exposure route). Studies in both sexes are more informative, because a single-sex study may miss cancers that are sex-specific. Outcomes should be measured after an appropriate latency period. Although rodent cancer studies, in general, need to last at least one year, there are exceptions that depend on the animal model and study design. Carcinogenicity studies in transgenic animals may need less than one year for tumor development. Adequate statistical power to detect an effect is based on sufficient numbers of animals in each treatment group surviving to the end of the study. This is particularly important when the incidence of induced tumors is low. The study duration and the rarity of the induced tumor in the animal model may be taken into consideration. | No or minor concern The study used an appropriate animal model with a sufficient number of animals and an appropriate study duration. Major to critical concern The study used an inappropriate animal model, or too few animals per group, or an insufficient study duration.

^a^ For experimental animal cancer studies, a rating response is given to each signaling question (integrating the response from any follow-up questions). Elaborations are meant to add clarification to the signaling questions.

^b^ Considerations for responses for other rating categories (e.g., “some” or “major”) may be defined in the protocol for the substance(s) under evaluation. Rationales are provided for all ratings. In general, critical concerns apply only to bias and to a few sensitivity questions that would exclude the study from review.

#### Exposure Conditions

The signaling questions in the exposure domain include one question that addresses the bias and one question on sensitivity (Table 4-3).

The bias question assesses the dose level, and the sensitivity question integrates information related to dose selection and exposure duration. Dose selection is considered as both a bias issue and a sensitivity issue. Aspects of exposure conditions that are specific to the candidate substance are defined in the protocol.

Table 4-3 Exposure: Questions and Responses

Signaling Questions^a^ | Guidance | Response Options^b^
Bias Questions
Dose selection
Is there concern that the dose level was too high (e.g., exceeded the maximum tolerated dose)? | Ideally, the authors should state their rationale for dose selection. For NTP chronic studies, dose selection is typically based on subchronic (90-day studies), and the high dose should not cause excess toxicity, for the duration of the study. | No or minor concern Minimal treatment-related survival effects were seen (other than mortality related to tumors). Tumors at the high dose were the result of a specific treatment-related effect. Major or critical concern Severe toxicity was seen in all treatment groups. Toxicity was so high that survival or body weight was greatly reduced. (Reduced survival due to tumors is not a concern.)
Sensitivity Questions
Is there concern that the conditions of exposure to the test agent did not provide sufficient sensitivity to adequately detect a neoplastic effect, if present? | The sensitivity rating integrates considerations of dose duration and selection. The selection of the dose may depend on the exposure duration. Ideally, exposure would last throughout or for a significant proportion of the animals’ lifespan (i.e., 1 to 2 years for rodents) depending on the model and route of exposure. However, the duration depends on the study design. For example, some studies (e.g., transgenic, stop exposure, or in utero exposure studies), depending upon the study design or the animals’ cancer susceptibility, do not require lifetime exposure. Doses should be high enough (i.e., achieving the maximum tolerable dose such as slightly decreased body weight gains or other signs of clinical toxicities) or based on dose-range finding studies. Evaluation of dose response can contribute to confidence in the study findings and allow for evaluation of potential effects at lower doses. Ideally, studies should use multiple doses; however, for the purpose of hazard identification, multiple doses are not required if the dose selection provides sufficient sensitivity. | No or minor concern The study included an appropriately high dose (as evident from signs of toxicity) and an adequate observation period. Major concern There is evidence that the combined dose level (i.e., too low) and duration (i.e., short) were not adequate to detect an effect in the animal model.

^a^ For experimental animal cancer studies, a rating response is given to each signaling question (integrating the response from any follow-up questions). Elaborations are meant to add clarification to the signaling questions.

^b^ Considerations for responses for other rating categories (e.g., “some” or “major”) may be defined in the protocol for the substance(s) under evaluation. Rationales are provided for all ratings. In general, critical concerns apply only to bias and sensitivity questions that would exclude the study from review.

#### Outcome Assessment and Measurement

The outcome domain consists of one signaling question (and related follow-up question) on the adequacy of the methods to assess tumor outcome in exposed and control animals (Table 4-4). This question addresses concerns about both bias and sensitivity. Evaluation of only a few organs for tumors, instead of all organs and tissues, can limit the study’s sensitivity. Although blinding generally is considered important to reduce bias in the assessment of subjective outcomes (such as behavior), nonblinding may be preferred for cancer outcomes, to determine normal background histology. The NTP uses an informed approach to histopathological evaluation in its toxicity and carcinogenicity studies (Sills et al. 2019). This principle applies to non-NTP studies, provided that the necropsy and histology methods used were adequate and consistent.

Table 4-4 Outcome: Questions and Responses

Signaling Questions^a^ Follow-up Question | Guidance | Response Options^b^
Outcome
Is there concern that the methods used to assess tumor outcome (necropsy, gross pathology, histology, or diagnosis) were not adequate to allow the effects to be attributed to the exposure? • Is there concern that not all treatment and control groups were assessed in the same way and in balanced blocks, to avoid bias? | Ideally, each study should include full gross necropsies of all tissues and histopathological examination of the majority of them. If details of the histopathological examination (e.g., cell type) are not reported, tumor type (and whether benign or malignant) should be reported. Ideally, the controls and all the treatment groups were treated the same. The control groups should be evaluated at necropsy to the same extent as the treatment groups. | No or minor concern Complete necropsies and gross pathology were reported for all tissues, and histopathological examination for most tissues. The control groups were treated exactly the same as the treatment groups except for the presence of the test substance. The conduct of the evaluation by the pathologists was sound. Major concern Pathology was assessed on only some tissues. Histopathology was not assessed in tumors. The controls were treated differently from the treatment groups.

^a^ For experimental animal cancer studies, a rating response is given to each signaling question integrating the response from any follow-up questions. Elaborations are meant to add clarification to the signaling questions.

^b^ Considerations for responses for other rating categories (e.g., “some” or “major”) may be defined in the protocol for the substance(s) under evaluation. Rationales are provided for all ratings.

#### Potential for Confounding

The confounding domain consists of two signaling questions and related follow-up questions and addresses the quality of the chemical characterization and any other potential sources of confounding that could influence the study outcome other than the substance under evaluation (Table 4-5).

Table 4-5 Potential Confounding: Questions and Responses

Signaling Questions^a^ Follow-up Questions | Guidance | Response Options^b^
Confounding
Is there concern about potential confounding? • What is the relative impact of the confounding? | Sources of potential confounding in animal studies are the use of an impure chemical that contains other potential carcinogens, inadequate animal husbandry conditions, and lack of monitoring for pathogens that may be linked to cancer. Food, water, and bedding should also be monitored for potential impurities. | No or minor concern The study used a pure testing agent without contaminants and adequate animal husbandry conditions. The test agent is representative of the substance under evaluation. Major or critical concern Strong evidence of the presence of carcinogenic contaminants in the testing agent or poor animal husbandry conditions will substantially compromise interpretation of the findings, and there are no data to evaluate the extent of the confounding. The test agent is not representative of the substance under evaluation and/or contains carcinogenic contaminants at levels high enough to compromise the interpretation of the results.
Is there concern that the characterization, dose formulations (e.g., homogeneity, purity, solubility, and stability), or delivery of the test agent (actual vs. desired dose) were not adequate to support attribution of any neoplastic effects to the substance under evaluation? | The purity of the test agent should be reported, and any contaminants listed. The test agent should be stable between making up of new stock solutions. Chemical stability, including in liquid media or feed, should be verified and be taken into account in formulation. Animals should be homogenously exposed to the agent.

^a^ For experimental animal cancer studies, a rating response is given to each signaling question (integrating the response from any. follow-up questions). Elaborations are meant to add clarification to the signaling questions.

^b^ Considerations for responses for other rating categories (e.g., “some” or “major”) may be defined in the protocol for the substance(s) under evaluation. Rationales are provided for all ratings.

#### Analysis

The analysis domain evaluates statistical methods and combining of tumor incidences and consists of two bias questions (Table 4-6). These questions address the methods for grouping the outcome (i.e., tumor types) and statistical methods to evaluate the findings. If statistical analysis was not performed, but tumor incidences were reported in enough detail, NIEHS can perform pairwise statistical calculations. Trend analysis across treatment groups (e.g., Cochran-Armitage trend test) can also be performed if there are three or more dose groups. It will be noted whether statistical analyses were performed by NIEHS.

Table 4-6 Analysis: Questions and Responses

Signaling Questions^a^ | Guidance | Response Options^b^
Combined tumors
Is there concern that different types of tumors were inappropriately combined in the analysis? | Analyses of benign and malignant tumors from the same tissue type should be reported both separately and combined. Tumors of the same cellular origin, which may appear at different organ sites (as seen with metastasis), should be combined. Organs that are of the same cellular origin and part of the same organ system can be combined, such as squamous carcinomas of the upper respiratory tract (nasal cavity, pharynx [throat], larynx [voice box], and bronchi) (McConnell et al. 1986). | No or minor concern Tumors of the same cellular origin are reported both individually and combined in the analysis. Major concern Tumor types of different cellular origins are combined, or tumors are not specified whether they are benign or malignant.
Statistical analysis
Is there concern that statistical analyses were inadequate or were not conducted to evaluate the results? • If statistical analyses were not conducted, were the results reported in sufficient detail to allow ad hoc analysis? | If statistical analyses were not reported, the study should at a minimum present incidence data for specific tumors, so that statistical tests (e.g., Fisher’s exact test for pairwise comparisons) can be conducted. If there is evidence of a decreased survival effect, the studies should use adequate statistical methods, such as the poly-3 test (Bailer and Portier 1988), to control for decreased survival. | No/minor concerns The study reported appropriate methods of analysis using relevant data. Analyses were adjusted for survival (e.g., poly-3 test) where relevant. Critical concerns There is strong evidence that reporting of data and analytical methods were so limited that the findings are not interpretable.

^a^ For experimental animal cancer studies, a rating response is given to each signaling question. (Elaborations are meant to add clarification to the signaling questions.)

^b^ Considerations for responses for other rating categories (e.g., “some” or “major”) may be defined in the protocol for the substance(s) under evaluation. Rationales are provided for all ratings.

### 4.2.3 Overall Assessment of Study Informativeness

The overall informativeness of a study considers both bias (i.e., systematic flaws or limitations that may compromise interpretation of the results) and study sensitivity. Studies having elements with major concerns may still be considered in a cancer hazard assessment, but the findings should be interpreted with caution. It should also be noted that some concerns about a study element (such as inadequate observation and/or exposure period or statistical power) would decrease the study’s sensitivity to detect an effect. If positive findings were described despite these limitations, these studies would inform a cancer hazard assessment. Studies with critical concerns about important issues generally are inadequate to inform the evaluation.

If a study’s information is inadequate for a reviewer to answer a specific question, the impact on overall study quality evaluation depends on the extent and importance of the missing information and is evaluated on a case-by-case basis. The study informativeness-level judgments can be found in Box 4-3. (See Section 4.4 for information on reporting data extraction and study informativeness.) These evaluations are brought forward to the evidence integration section.

Box 4-3 Study Informativeness-level Judgment

High: no or minimal concerns about most potential biases, high or moderate sensitivity.

Moderate: low, minimal, or some concerns about most potential biases.

Low: major concerns about several biases, sensitivity rating varies. Depending on the direction and distortion of the potential biases, the study may still be informative for the cancer hazard evaluation but should be viewed with caution.

Inadequate (very rare): critical concern about any bias; sensitivity rating varies. Severe insensitivity.

## 4.3 Evidence Evaluation and Integration

This section outlines the approaches to integrating the evidence across studies to identify exposure-related cancer sites (Section 4.3.1), evaluating external validity (Section 4.3.2), applying the RoC listing criteria, and reaching a level-of-evidence conclusion (sufficient or not sufficient) on the carcinogenicity of the substance from experimental animal cancer studies (Section 4.3.3).

The conclusions regarding the assessment of study informativeness are carried forward to the cancer hazard evaluation, and the studies with the greatest utility to inform the cancer hazard evaluation (as described in Section 4.2) are given the most weight. All studies with low, moderate, or high informativeness are brought forward to the evidence integration, we Studies with inadequate ratings are usually not brought forward to the evaluation, but this is rare.

### 4.3.1 Interpretation of the Evidence from Individual Studies

The findings of each study are interpreted with respect to their limitations and strengths (identified as described in Section 4.3.1). For example, positive findings from studies receiving poor ratings for sensitivity (such as low statistical power or short duration) should not be discounted, because other factors are considered as well when determining whether an effect (e.g., increased incidence of a specific tumor type) is treatment related. The factors considered include statistical significance with respect to controls and dose-related trends, preneoplastic lesions, lesion progression, decreased latency, tumor multiplicity, tumor incidence, historical control range, animal survival, species, sex, strain, and rarity of tumor. For instance, an uncommon tumor type could be deemed treatment-related without a statistically significant increase in incidence. It is important to note that the shape of the dose-response curve may vary (i.e., may not always be monotonic), and various factors (e.g., metabolism and toxicokinetics of the substance or differences in animal survival among the treatment groups) can affect the shape of the curve (IARC 2019). In evaluating potential confounders in an individual study, one should consider the magnitude of the effect, the adequacy of the controls, and whether a potential confounder could modify effects across exposure groups.

### 4.3.2 External Validity

External validity addresses the extent to which conclusions from one study can be generalized to other situations (i.e., the relevance of experimental animal data to humans). Studies testing only one sex of animal may have limited validity for the human population, and further evaluation may be needed. When interpreting the relevance of experimental animal study findings consideration should be given to the route of exposure, substance disposition, and mode of action. Although the relevance to human exposure is considered, studies using exposure routes that are not common in human exposure are not usually excluded from the cancer hazard assessment; however, this issue may be addressed on a case-by-case basis and would be described in the substance evaluation protocol. Findings of tumors at a similar tissue site by different routes of exposure strengthen the evidence for carcinogenicity.

Neoplasms observed in experimental animals are considered to be relevant to humans unless there is compelling evidence indicating that they occur by a mechanism that does not operate in humans. In other words, it is the cancer mechanism that informs the evaluation of potential carcinogenicity in humans. For example, the occurrence of neoplasms in tissues that do not occur in humans (e.g., the rodent forestomach and rat Zymbal’s gland) might be relevant to humans. In contrast, some tumors in rodents may occur by mechanisms that may not be relevant to humans, such as kidney neoplasms that occur exclusively from the production of male-rat-specific alpha2u-globulin. Mechanistic and other relevant data are evaluated in a separate section of the monograph and are one of the points to be considered in assessing the human relevance of a tumor outcome.

The following points should be considered in assessing the relevance of an experimental animal cancer study for evaluating the potential for human carcinogenicity:

- Relevance of the route of exposure.
- Relevance of the species, sex, or animals’ age.
- Relevance of the mechanism of tumor formation.

### 4.3.3 Evidence Integration Across Animal Cancer Studies

The final steps in evaluating evidence from experimental animal cancer studies are integrating the evidence for treatment-related tumors across studies, applying the RoC listing criteria (see below), and reaching a level-of-evidence conclusion from studies in experimental animals.

#### RoC Listing Criteria for Evaluating Carcinogenicity from Studies in Experimental Animals

##### Sufficient Evidence of Carcinogenicity from Studies in Experimental Animals:

An increased incidence of malignant and/or a combination of malignant and benign tumors

- In multiple species, or
- At multiple tissue sites, or
- By multiple routes of exposure, or
- To an unusual degree with regard to incidence, site, or type of tumor or age at onset.

The first step in evidence integration is to evaluate the evidence across studies for each cancer site of interest. For most databases, heterogeneity in findings is often explained by differences in experimental conditions (e.g., species, sex, strain, doses, duration, route), and few studies have been conducted using exactly the same experimental conditions. As mentioned above, the most informative studies (highest quality and sensitivity) are given the most weight, and positive findings from these studies are considered to provide evidence of treatment-related tumor effects. Moderate- and low-quality studies can also be used in the assessment, especially when it is unlikely that biases (moderate) in the studies would cause false-positive results. Replication of findings across several studies also increases confidence in treatment-related effects.

In general, the RoC criteria for sufficient evidence of carcinogenicity from studies in experimental animals are fulfilled by: (1) two studies (by different exposure routes or in different species) reporting positive findings of malignant or combined malignant and benign tumors or (2) one study reporting positive findings at multiple tissue sites. In addition, positive findings from one robust study can fulfill the criteria if the tumors are rare, have an early onset, or have a high incidence. The spectrum of neoplastic responses, from preneoplastic lesions and benign tumors to malignant neoplasms of a specific tumor type, is relevant for the evaluation of whether benign tumors observed at increased incidences are likely to progress to malignancy.

## 4.4 Reporting and Data Extraction

This section provides information on reporting (e.g., related to extracting data on the studies and their findings) and documenting the key steps in the cancer hazard evaluation (i.e., documenting the framework, assessing study informativeness, and evaluating and integrating the evidence). The cancer hazard evaluation is captured in text, tabular, and graphical format.

### 4.4.1 Data Extraction

Data are extracted from individual animal cancer studies into a database or web application (such as Table Builder, Shapiro et al. 2018) in a systematic manner using standardized instructions and questions. The database is organized by study methods, including study design (e.g., species, strain, route), exposure methods (e.g., agent, route, dosing regimens), outcome methods (e.g., tumor incidence, animal survival), information related to evaluating confounding (e.g., animal husbandry methods, chemical purity), and statistical analyses. Extracted study results include the tissue type and histological classification, animal survival, tumor incidence, and statistical significance. If the study authors did not perform statistical analyses, NIEHS will conduct pairwise analysis of neoplasm incidence relative to control group(s) (e.g., Fisher’s exact test) and trend analysis across treatment groups (e.g., Cochran-Armitage trend test) and will note that these analyses were performed by NIEHS.

Quality assurance of data extraction and database entry is done by a reviewer independent of the data extractor. Any discrepant entries are resolved through mutual discussion with reference to the original data source. The extracted data are presented as tables in the monograph and can be downloaded into Excel for additional analyses or visualization.

### 4.4.2 Reporting

The methods for reporting will be determined in part by the substance(s) under review. The following points provide guidance for reporting cancer studies in experimental animals and presenting preliminary level-of-evidence conclusions for animal studies:

- An overview of study characteristics initially included in the evaluation.
- A scientific discussion of study informativeness across studies, organized by bias and study sensitivity domains.
  - Study informativeness for each study typically is presented in tabular format (e.g., downloaded from web-based software such as Table Builder). (See published RoC monographs for reporting examples.)
  - Reporting of the data for individual studies (e.g., study description and findings) in tabular format downloaded from web-based software such as Table Builder (see Box 4-4 for reporting examples from published RoC monographs).
  - Narrative discussion of the assessment across studies, organized in part by the key questions to be addressed in the protocol (e.g., at what tissue sites did cancer occur?).
  - Discussion highlighting any key issues noted for the type of exposure(s) and tumor outcomes.
  - Findings across studies are presented in tabular or graphical formats.

Box 4-4 Examples of Reporting in Report on Carcinogens Monographs

Haloacetic acids (Section 4 and Appendix C) (https://ntp.niehs.nih.gov/ntp/roc/monographs/haafinal_508.pdf)

Antimony trioxide (Section 5 and Appendix D) (https://ntp.niehs.nih.gov/ntp/roc/monographs/antimony_final20181019_508.pdf)

Cobalt and cobalt compounds (Section 5 and Appendix D) (https://ntp.niehs.nih.gov/ntp/roc/monographs/cobalt_final_508.pdf)

The level of evidence for carcinogenicity from studies in experimental animals (sufficient, not sufficient) and rationales for the conclusions are presented in evidence-based tables (see Table 4-7 for a template and Table 7-2 for an example.)

An evidence-based table captures the overall assessment and is brought forward to the overall evidence integration to reach a preliminary listing recommendation (see Section 7).

Table 4-7 Template Example for Summarizing the Assessment of Key Evidence from Animal Studies

Exposure | Outcome | Evidence Streams | Strength and Limitations | Assessment
Substance | Cancer type or across cancers | Number and type of animal cancer studies Animal models (e.g., route, species) | Summary of most influential biases (direction, magnitude, impact) across studies by model, route, or other relevant grouping | Exposure-related cancer sites, common cancer sites across groups of chemicals Information relevant to evidence integration

## References

Bailer AJ, Portier CJ. 1988. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 44(2):417–431. 10.2307/2531856 3390507
International Agency for Research on Cancer (IARC). 2019. Preamble to the IARC monographs. Lyon, France: International Agency for Research on Cancer. https://monographs.iarc.who.int/iarc-monographs-preamble-preamble-to-the-iarc-monographs/
McConnell EE, Solleveld HA, Swenberg JA, Boorman GA. 1986. Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 76(2):283–289. 3456066
Shapiro AJ, Antoni S, Guyton KZ, Lunn RM, Loomis D, Rusyn I, Jahnke GD, Schwingl PJ, Mehta SS, Addington J, et al. 2018. Software tools to facilitate systematic review used for cancer hazard identification. Environ Health Perspect. 126(10):104501. 10.1289/EHP4224 30392397
Sills RC, Cesta MF, Willson CJ, Brix AE, Berridge BR. 2019. National Toxicology Program position statement on informed (“nonblinded”) analysis in toxicologic pathology evaluation. Toxicol Pathol. 47(7):887–890. 10.1177/0192623319873974 31522628