# 3 Evaluation of Human Epidemiology Studies

## Summary

The aim of this part of the cancer hazard evaluation is to determine the level of evidence for carcinogenicity (sufficient or limited) from human cancer epidemiology studies. Systematic review and evidence-integration methods are used to conduct the evaluation.

The first step is to develop a human health hazard framework for epidemiology studies (Section 3.1). This involves developing a scoping review (a structured literature search to determine the extent of the body of literature on a particular topic, as well as identify key issues and potential data gaps) and evidence map (a visual representation of literature scoping); creating and refining a Population, Exposure, Comparison group, and Outcome (PECO) statement, to define the exposure(s) and outcome(s) under review; and developing a study protocol (a detailed description of reasoning, methods, and considerations for evaluating study informativeness).

The second step (Section 3.2) is to evaluate each study (irrespective of its findings) and determine its informativeness (the study’s ability to inform the cancer hazard evaluation, somewhat analogous to study utility). This involves a domain-based approach to assessing biases (an evaluation of internal validity that assesses the potential that a specific bias is present and, if so, the direction and magnitude of the bias and its impact on the study findings) and study sensitivity (the study’s ability to detect a true effect) and making an overall judgment about the study’s informativeness. It is important to note the direction and magnitude (or distortion) of a potential bias are considered in the judgment calls when evaluating the potential for bias for each study.

The third step is to integrate the evidence to reach health hazard conclusions for each cancer type based on the human epidemiology studies (Section 3.3). This includes an evaluation of confidence (e.g., moderate or strong, some, null, inconclusive) in the study’s findings (evidence for or against an association between the exposure and the outcome). To aid this step, a meta-analysis may be prepared, if feasible. The evaluation of the level of confidence integrates the study findings with bias impact analyses (quantification or qualitative assessment of the overall impact of one or more biases on the identified association, informed by the bias analysis), followed by evidence integration (evaluating the evidence across studies) to determine whether a credible association exists between exposure and cancer and, if so, whether alternative explanations (chance, bias, or confounding) can be ruled out with reasonable confidence.

The Report on Carcinogens (RoC) uses several approaches to integrate evidence across all epidemiology studies for a particular cancer type. These approaches use triangulation (integration of data from different methods, designs, theoretical approaches, and unrelated sources of bias to see whether the evidence converges on one conclusion) methods and guidelines for causality such as Bradford Hill (e.g., the strength of the association, consistency across studies, evidence of an exposure-response gradient, and temporality of exposure). Meta-analysis (a statistical method for combining the results of several studies) may be used to explore heterogenicity and evaluate consistency when appropriate. Lastly, the level of evidence (sufficient, limited, or inadequate) for the carcinogenicity of the substance from studies in human populations is determined by applying the RoC criteria to the body of evidence. The assessment is made for each cancer outcome, and the overall conclusion is based on the highest level of evidence.

## Introduction

This section describes the methods for systematic review and integration of evidence from human epidemiology studies to assess the level of evidence for the carcinogenicity (primarily) of a substance, agent, mixture, or exposure circumstance (collectively called “substances”). The approach to the cancer hazard evaluation of human studies has been updated from the 2015 RoC Handbook and is informed by methods of systematic review developed by other organizations and groups, by standard epidemiological principles (e.g., IARC 2021; Rothman et al. 2008; Sterne et al. 2014; USEPA 2022), and with input from epidemiologists and other scientists developing systematic review procedures. Although this section focuses on cancer epidemiology studies, the study informativeness evaluation questions and guidelines also apply to cancer mechanism studies with human participants. Section 6 describes the methods for evaluating mechanistic endpoints.

The key scientific questions and major components in the cancer hazard evaluation are described below.

### Key Questions for Cancer Hazard Evaluations

#### Primary Questions

- Is there a credible association between exposure to the substance and cancer (for specific cancer types or all cancers combined)?
- If so, can the association between exposure to the substance and cancer types be reasonably explained by chance, bias, or confounding?
- What are key scientific issues for evaluation of the studies?

#### Secondary Questions (Scoping Phase)

- Which epidemiologic studies should be included in the review?
- Which cancer types should be the focus of the review?
- What are the potential confounders (including co-exposures) important for assessing the association between the substance and specific cancer types?
- What are the key issues for evaluating the quality of the exposure assessment for the substance and cancer type under consideration, such as the methods applied, the time windows of exposure considered, the most relevant exposure metrics, and the timing of the assessment? Is there biological or mechanistic information to inform these metrics?
- What are the methodological strengths and limitations of these studies?

### Process and Components of the Cancer Hazard Assessment

In general, the cancer hazard assessment for epidemiology studies consists of three major components, as shown in Figure 3-1.

#### Components of the Cancer Hazard Assessment of Epidemiology Studies for the RoC

- Develop the cancer hazard evaluation framework (Section 3.1):
  a. Develop and execute a literature search strategy to search, identify, and map the literature.
  b. Develop the protocol that captures the approach to conduct the assessment.
- Evaluate the informativeness of the epidemiology studies (Section 3.2).
- Evaluate and integrate the evidence to reach cancer hazard conclusions from the human studies (Section 3.3).

Figure 3-1

Components of the Assessment of Epidemiology Studies for the Cancer Hazard Evaluation

The first step is to develop a framework for the review. This involves scoping and mapping the literature, refining the criteria or the database for inclusion (e.g., the PECO statement), identifying key issues, and developing the methods. Next, through a structured approach using questions and guidelines, the included studies are evaluated for their ability to inform the cancer evaluation based on the bias assessment (internal validity) and study sensitivity (the ability to detect a true effect, see Section 3.2.2 and Table 3-9). The last step includes evaluating the individual studies for the level of confidence in their findings and the impact of bias (see Section 3.3.1) and integrating the evidence across studies using formal approaches and guidelines to reach a hazard conclusion judgment (see Section 3.3.2).

## 3.1 Cancer Hazard Framework Development

Conducting a cancer hazard assessment for a substance begins with scoping and problem formulation activities to develop the research question, the initial PECO framework, literature search strategies, and creation of a protocol for the cancer hazard evaluation of a specific substance (Figure 3-2). Section 1 discusses scoping and problem formulation for the overall cancer hazard evaluation (including selecting the substance and developing the initial PECO), whereas this section focuses on methods related specifically to the review of epidemiology studies (e.g., identifying, selecting, mapping the literature, redefining the PECO, identifying issues of concern, and developing the protocol). The scoping activities and systematic evidence maps are usually not reported as an independent review.

Figure 3-2

Developing the Cancer Hazard Evaluation Framework

Early steps in the process are to identify technical advisors with subject-specific expertise who can provide input throughout the systemic review, and to obtain scientific and public input via webinars, information groups, or other relevant mechanisms. Examples include past webinars on pentachlorophenol and trichloroethylene and a workshop on night shift work and light at night. The process is necessarily iterative (i.e., there may be several cycles of literature searches and evidence mapping).

### 3.1.1 Literature Search Strategy, Study Selection, and Systematic Evidence Mapping

The initial PECO statement (which was informed by scoping activities) indicates the first step is to develop and conduct a targeted literature search strategy (in consultation with an information specialist) and associated inclusion/exclusion criteria. The second step is to select and map the primary epidemiology studies from this database of identified studies. As per the RoC process, studies must be peer reviewed and publicly available. In addition to primary epidemiology studies, the review will include supporting literature (e.g., independent exposure assessment studies) that may be relevant for interpretation of the epidemiology studies. Toxicological and mechanistic data may inform the evaluation of human studies, e.g., biologically relevant exposure metrics, latency, tumor subtypes, and effect modifiers (see Sections 4, 5, and 6). Recent high-quality meta-analyses may also be included in the evaluation.

Searches are conducted in PubMed and at least one other database (such as Scopus or Web of Science) using search terms for the substance and exposure scenarios related to the substance combined (using the Boolean operator “AND”) with search terms for epidemiology studies and with search terms for the outcome (cancer). The RoC staff maintains standard lists of search terms (https://ntp.niehs.nih.gov/ntp/roc/handbook/rochandbookappendix_508.pdf) for epidemiological concepts and cancer types found on the RoC website. Table 3-1 lists some general search concepts used to identify epidemiology and cancer studies in most evaluations. Search terms may be modified (usually to a minor extent) on a case-by-case basis, depending on the specific substance. Section 6 describes search strategies specific to mechanistic studies in humans.

Table 3-1 Examples of Concepts Used in Searches for Cancer Epidemiology Studies in Humans

PubMed, Scopus, and Web of Science | | MeSH Terms Used in PubMed
Epidemiology Terms | Cancer Terms | Epidemiology Terms | Cancer Terms
Case-control Cohort Case-referent/cohort Case-report/series Cross-sectional^a^ epidemiology Meta-analysis [publication type] Systematic review [publication type] Workers Workmen Ecological study Randomized controlled trial | Cancer Leukemia Lymphoma “lymphohematopoietic cancer”^b^ “multiple myeloma” Neoplasm Tumor | Epidemiological studies Epidemiological methods Occupational exposure/ Adverse effects Epidemiology[subheading] Etiology[subheading] | Neoplasms

Note that these are examples of search terms, and not the detailed or fully developed search strings used in the actual literature search found in the search string document (https://ntp.niehs.nih.gov/ntp/roc/handbook/rochandbookappendix_508.pdf) on the RoC website.

^a^ May be useful for specific candidate substances and tumor types when a temporal sequence can be established (e.g., the presence of a virus before detection of cancer), and reverse causation can be ruled out with reasonable confidence.

^b^ More specific search terms for lymphohematopoietic cancer may be developed for specific candidate substances.

Relevant literature may also be identified from sources such as authoritative reviews and citations from identified publications, and searches may also be conducted on specific topics. In addition, to supplement our standard searches and searches of authoritative reviews, we have created a custom library of PDFs of occupational case-control studies identified through searches of the three literature databases using terms for occupational exposure, case-control studies, and cancer. This library was created to identify studies that report on a large number of substances, which are not identified in the title or abstract, which is common in occupational case-control studies. Full-text searches of this library are conducted (using Adobe Acrobat full-text search tools) to identify cancer studies of substances or chemicals that may not have been identified through the database searches alone.

Citations retrieved from literature searches are uploaded to a web-based systematic review software application (such as Health Assessment Workspace Collaborative [HAWC], SWIFT Active Screener, and SWIFT Review) and screened by reviewers using predefined inclusion/exclusion criteria based on the initial PECO statement. For reviews with large databases, machine-learning software, such as SWIFT Active Screener, may be used. SWIFT Active Screener has been shown to have a high rate of recall (sensitivity) while minimizing the number of articles screener (Howard et al. 2020). In general, primary studies may be excluded if they (1) do not adequately evaluate exposure specifically to the substance, and (2) do not evaluate health effects related to carcinogenicity. Inclusion of studies such as case reports, case series, cross-sectional, or ecological studies is decided on a substance-by-substance basis and will be delineated in the protocol (see below).

For planning the hazard assessment, it may be useful to visualize the literature retrieved. Studies may be tagged by keyword in review software programs (e.g., HAWC). The evidence for included studies may be mapped according to cancer type, exposure source (e.g., occupational or environmental), exposure assessment method, study design, or other relevant issues. Systematic evidence maps present a broad scope of the literature in a visual format and can also be visualized in an interactive format, such as on platforms created using Tableau software. During the problem formulation stage, these maps can be key for deciding which elements (e.g., study population characteristics, exposure metrics) to carry forward to the systematic review, how many studies are available for a specific cancer type and can be used to inform or refine the PECO statement and protocol. For example, evidence maps may help identify on which study characteristic to conduct stratified analyses.

Final selection of studies for inclusion in the systematic review is based on the final PECO statement. For example, the systematic review and hazard assessment may be restricted to cancer types with an adequate database that suggests a cancer hazard; findings for cancer types with sparse or inconsistent data may be briefly summarized. Note that there is no formal guidance on what constitutes an adequate number of studies for a cancer hazard evaluation. For example, a single study reviewed during the scoping process may be influential for reaching a hazard conclusion at the evaluation stage if it is a large multicenter study (i.e., replicated in different study populations), conducted in populations with high exposure levels and large exposure contrasts, adequately controlled for confounding, and presents multiple sensitivity analyses to demonstrate with reasonable confidence that any associations detected are unlikely to be due to chance, bias, or confounding.

There is also no formal guidance on which study design is considered the most informative for causal inference; this must be judged on a substance-by-substance basis (Arroyave et al. 2021; Steenland et al. 2020). For example, ecological studies with large exposure contrasts have been influential in evaluating the carcinogenicity of arsenic in drinking water (IARC 2004; 2012). Cross-sectional studies and case series/case reports are generally not informative for cancer hazard assessment and will be decided on a case-by-case basis. By design, cross-sectional studies assess exposure and outcome simultaneously; therefore, it is challenging to establish whether the estimated exposure precedes disease occurrence (e.g., a temporal association), particularly for studying short-lived biomarkers and long-latency diseases. Cross-sectional studies are carefully assessed for their accuracy in assigning individuals to exposure levels or categories (considering the potential for reverse causation or recall bias); and for whether prevalent disease is an appropriate proxy for disease incidence (Savitz and Wellenius 2023). Typically, cohort studies (and their variants) and case-control studies have provided the bulk of the evidence (IARC 2019).

### 3.1.2 Protocol Development

The protocol describes the systematic review methods for evaluating the human cancer studies and may be part of the monograph protocol and may be published on the RoC website as a separate document after peer review. It consists of the following sections: (1) developing the framework, which provides information on the objectives, identifying and mapping the evidence, the PECO statement, and substance-specific scientific issues, (2) detailed methods for evaluating study informativeness, such as the potential for exposure and outcome misclassification, confounding, and other potential biases that may be important in evaluating the findings for the hazard evaluation and (3) methods for evaluating and integrating the evidence across studies. Information on data extraction and the roles of the evaluation team may also be included. Developing the protocol requires understanding the types of studies and scientific issues that are available to inform the hazard assessment and requires background research on the substance, the cancer type(s), and any co-exposures and their measurement, taking into consideration input from subject-matter and methodologic experts.

#### Identification of Potential Confounders, including Co-exposures

A key question for reaching a level-of-evidence conclusion from observational studies is whether any association between exposure and cancer is likely to be explained by confounding. Potential confounders are factors that are moderately to strongly associated with both exposure and the disease outcome(s) of interest. A confounder is not an intermediate in the disease pathway (Figure 3-3). For example, in cohort study designs, confounding occurs when the comparison groups under study (e.g., the exposed vs. the unexposed groups) have different background risks of disease (Pearce et al. 2007), thereby mixing the association of interest with the effects of other factors.

Figure 3-3

Diagram to Explain Confounding in the Exposure-Outcome Relationship

Adapted from Jager et al. 2008, this diagram visualizes how a factor can confound an exposure-outcome relationship of interest.

Potential confounders, including co-exposures, may be quantified or noted by the study authors or identified from authoritative sources, literature review, or consultation with experts during the planning phase. Authoritative sources of risk factors include substances listed in the RoC, such as the 15th RoC Dashboard (https://ntp.niehs.nih.gov/go/RoC15data) (NTP 2023), the International Agency for Research on Cancer (IARC), the National Cancer Institute, the American Cancer Society, and the World Cancer Research Fund. Peer-reviewed and published evidence that a risk factor is also associated with the exposure of interest is critical for its being considered a potential confounder.

Co-exposures are environmental and/or occupational exposures that study participants may be simultaneously exposed to and are correlated with the exposure of interest. Whether a given co-exposure should be considered as a potential confounder depends on the availability of evidence that the co-exposure is potentially associated with a specific cancer(s) of concern. Occupational co-exposures, as assessed in the general population (e.g., population-based, or hospital-based case-control studies), may be of less concern. The broad diversity of jobs among study participants and the low prevalence of specific jobs and exposures (Cocco et al. 2013) reduces the sensitivity to detect an association. Visual diagrams (e.g., directed acyclic graphs) may be used in some cases to help identify potential confounders and to identify whether confounders were controlled for correctly in the analyses (e.g., control for factors on the causal pathway is inappropriate).

The estimated impact of potential confounding bias on study results may vary by confounder (Steenland et al. 2020). Importantly, reviewers should distinguish major or key confounders from confounders with minimal impact. Major or key confounders are factors that are expected to substantially impact the magnitude and/or direction of the study results. Note that a factor identified as a confounder can also be an effect modifier (i.e., a factor that differentially impacts the magnitude of effect of an exposure-outcome relationship). Within the protocol, key confounders are identified apart from factors expected to weakly impact the magnitude or direction of the study results. Use of causal diagram tools (e.g., www.dagitty.net) may aid in visualizing and identifying key confounders across studies having similar populations.

#### Background Research on Exposure Metrics

Characterization of exposure in observational studies involves various tools and methods for assigning participants to exposure groups, levels, or categories. Several examples relevant to the evaluation of cancer epidemiology studies by exposure type are presented in Table 3-4. Relevant types of exposures can be broadly classified as follows:

- Occupational exposures: Assessment is often based on job-exposure or job-task-exposure matrices or expert assessments that link the subject’s occupational history (e.g., job or department titles, task descriptions and frequency, duration of employment) with workplace exposure data (e.g., monitoring data, production methods or applications, or protection procedures). Biological monitoring data and environmental monitoring data (e.g., levels of a chemical in facility air, personal monitors such as radiation badges) may also be used to assess occupational exposure.
- Environmental exposures: Assessment is often based on measurements of the likely source of individual exposure (e.g., the concentration of an air pollutant) and/or biological monitoring data. In these studies, a range of relevant surrogate measures may be included and can be supplemented through the use of questionnaires to establish individual patterns of exposure (e.g., consumption of drinking water or duration of residence near a pollution source). Assessment can also be conducted at the individual level through the use of personal monitors or by measuring biomarkers.
- Personal behaviors and related exposures: Assessment of other types of nonoccupational exposures (e.g., biological agents, consumer products, or personal behaviors such as smoking or diet) typically relies on a combination of one or more methods, including medical and clinical data or records, biological monitoring (e.g., for cotinine in urine), or participant questionnaires collected at the individual level.
- Social determinants of health: Examples include race, gender, socioeconomic status (SES), healthcare access, and community-level factors such as community cohesion and built environment (e.g., transportation access, green space). Race and/or ethnicity are typically used as proxies for racism; biological or self-reported sex for gender or gender roles; and education and/or income for SES; however, these proxies may not capture the determinants of interest. Many individual-level factors are usually self-reported or obtained from records (e.g., medical, occupational); indicators of community-level factors may be obtained from a range of administrative and governmental databases, including census data, although an increasing number of tools are also available (see, for example, https://www.cdc.gov/socialdeterminants/data/index.htm)

The ability of epidemiology study findings to inform the hazard assessment depends on the type and quality of assessment used to characterize exposure, a detailed understanding of relevant methods used to collect and process exposure data, and the exposure metrics and timing of assessment. A guide to identifying potential biases in the exposure characterization of a specific substance is provided in Table 3-4 and Table 3-5, found in Section 3.2.

In addition to the considerations above, when at all possible, selection of the most appropriate exposure metrics should be done with consideration of the underlying biologic mechanism. Concepts such as latency, susceptibility windows, the reversibility of the exposure or effect, and peak exposure are important to consider when selecting the exposure metric (Checkoway et al. 2019; Smith and Kriebel 2010). Although these considerations and an understanding of the underlying biology are important, in epidemiology studies; however, some or all of these factors may not be known.

Therefore, searches for information regarding the most appropriate exposure metrics and methods used to characterize exposure should be conducted in the context of both the substance under evaluation and the study design, along with an understanding of the underlying mechanisms when available. This includes method validation studies, as well as environmental scenarios related to exposure, consumer products and uses, production methods, anticipated levels of exposure to the substance, and interpretation of various exposure metrics, such as intensity, duration, or calendar years employed. For example, for studies assessing exposure using biological markers, it is important to know the specificity of the exposure biomarker of interest and how the magnitude, frequency, and timing of exposure are relevant to the etiologic time (Smith and Kriebel 2010) interval. Similarly, it is important to identify relevant time windows of exposure in relation to the cancer type(s) evaluated.

#### Background Research on the Outcome Assessment

##### Cancer Types

Prior to the outcome assessment, it is important to consider the methods used to obtain data on cancer incidence, vital status, and cause of death; the expected rates of cancer incidence, mortality, and survival for the cancer types of interest; and the implications of survival rates for interpreting mortality or incidence rates. Because the completeness and reliability of cancer registry incidence data can vary (e.g., by collection methods, country or region, and calendar period), relevant registries should be researched prior to study evaluation. For instance, the United States has no central national cancer registry; therefore, it can be difficult to obtain complete follow-up information for a cohort, especially for nationwide studies and for individuals who migrate from one area of the country to another. Currently, the U.S. Surveillance, Epidemiology, and End Results (SEER (https://seer.cancer.gov/)) (NCI 2022) database and other relevant data [e.g., Globocan (https://gco.iarc.fr/today/home) (IARC 2022)] are used to understand expected rates of incidence, mortality, and survival for specific types of cancer in a given country or region. However, future RoC reviews may make use of an effort to create a pooled virtual registry that is currently underway. Diagnostic methods, criteria, and coding systems for cancer, such as the International Classification of Diseases cancer codes, change over time. These changes may have implications for particular cancer types and subtypes (especially some of the lymphohematopoietic cancers) and should also be researched prior to outcome assessment. Finally, the latency period between etiologically relevant periods of exposure and cancer diagnosis can differ among various types of cancer and patterns of exposure, and each should be researched prior to the evaluation. This will provide information pertinent to understanding a study’s sensitivity to detect an effect.

##### Mechanistic Evidence from Human Molecular Epidemiology Studies

In general, mechanistic outcomes will be biological effects identified as the key characteristics of carcinogens (Smith et al. 2016). Studies in exposed humans that report outcomes relevant to the key characteristics of carcinogens are emphasized when available. Research on issues related to evaluating these outcomes will be part of the mechanistic section of the protocol, noting any issues that may be pertinent to the evaluation of human epidemiology studies.

#### Meta-analysis

If relevant and feasible, a meta-analysis may be conducted as a part of the cancer hazard evaluation. A meta-analysis may be indicated when there are a sufficient number of studies with similar exposure and outcome measures than can be combined. A meta-analysis may be useful as a quantitative means of exploring heterogeneity and can complement the qualitative cancer hazard assessment. If a meta-analysis is planned, the protocol will include the methods for conducting the meta-analysis, including the PECO statement (which may differ from the overall PECO for hazard evaluation), the statistical methods, and methods for exploring heterogeneity (including direction of bias, key issues, and effect modifiers, which may be informed by evidence mapping). More information on key issues to consider in a meta-analysis protocol can be found in Section 3.3.2, under the meta-analysis and meta-regression subsection.

In some circumstances, we may rely on published meta-analyses provided they are up to date, free of biases and well-conducted by authoritative research groups that are free of conflicts of interest. Meta-analyses will be evaluated individually and may not be included in the assessment if they are not deemed relevant.

Table 3-2 Summary of Exposure Data Collection Tools and Assessment Methods Commonly Used in Epidemiology Studies

Exposure Measurement | | Definition | Occupational Exposures | Environmental Exposures | Personal Behaviors and Social Determinants of Health (SDH)
Data Collection Tools
Self or Proxy-report | Interview (mail, web, in-person, or telephone) Questionnaire | Series of questions on specific exposure or circumstances that can be used to infer exposure | Specific chemicals or agents Job title, tasks, or history | Specific environmental contaminants Geographical location | Use of specific consumer products or medications, personal behaviors, and proxy for SDH Questionnaires are available for assessing some factors, such as perceived racism or discrimination
Records | Routine or population data | Data routinely collected for other purposes than the study of interest, such as a census | Usually used in population-based studies Information on workers (usually just job title) but not on workplace conditions | Aggregated data on substances in the environment (e.g., chemicals, pesticides) | Aggregated data from population surveys on personal behaviors (e.g., NHANES)
Records | Administrative or specific | Data collected for a specific purpose, such as employment, health, or school records; often used for specific cohorts, but also in population-based studies | Detailed information on specific workplace exposures and detailed job history for that job | Data collected to describe statewide, regional, or national land, water, or groundwater characteristics | Medical (or occupational) records, which in some cases may have information on demographics, medication or personal behaviors related to disease
Environmental Monitoring | Area or spatial | Involves the collection of one or more measurements used to assess the status of an environment | Air monitoring over a defined time period in a specific job or work areas in plants | Measurements of water, soil, or air in various environments over time and space and in the vicinity of study participants | NA
Environmental Monitoring | Personal | Devices designed to collect data on personal environmental exposures occurring very close but external to the body | Devices used to collect data on substances in the personal airspace of workers | Personal monitoring devices measuring individual exposures, such as silicone bracelets | Devices used to collect data about diet, medications, and other personal behaviors
Biomonitoring | Biological sampling | Examples include urine, serum, plasma, saliva, breast milk, hair, nails, cells, or other tissues collected for the purpose of measuring a specific substance or exposure | Biological samples (often urine or serum) collected from workers | Biological samples collected from individuals living in study areas or in controlled indoor experiments | Biological samples collected from individuals in a study
Methods Used to Assess Collected Data
Expert Assessment | Job-exposure matrix (JEM) | Standardized method used to translate job information obtained from administrative records into specific exposures for characterizing individuals as exposed or nonexposed, allocating the same exposure estimate to all workers within a job category and time period | Population-specific JEMs or general population JEMs can be developed based on questionnaire data; usually conducted for assessing exposures in occupational studies | NA | NA
Expert Assessment | Expert assessment | Conducted by industrial hygienists or occupational experts based on case-control questionnaire data and historical information about past exposures for various locations and time periods | Usually conducted for occupational studies to assess exposure on the job; can be based on administrative records or questionnaire data | NA | NA
Modeling | Dosimetric model | A conceptual or mathematical representation of the exposure process; similar to using appropriate weights for each subject’s exposure history, taking into account biological variability (Smith and Kriebel 2010) Outputs can be an exposure concentration or the amount of a chemical that is absorbed into the body, including a dose at a target tissue or organ | May include biomarkers, toxicokinetic, and physiological data to estimate individual dose | May incorporate elements of environmental and biologic fate, population activity patterns, and biomonitoring | May incorporate elements such as population activity patterns and biomonitoring
– | Other exposure models | Other mathematical models, such as cumulative, aggregated, probabilistic, deterministic, or stochastic models, used to best represent the exposure process and grounded in one or more exposure measures and/or exposure-response relationships Used to more accurately reflect more complex exposure scenarios, when other exposure methods are not feasible or require further characterization | May incorporate elements of biomonitoring (e.g., biomarkers) May be used to model exposure metrics such as e.g., cumulative, peak, frequency, or average exposure | May incorporate elements of environmental and biologic fate, population activity patterns, and biomonitoring | May use algorithms and software to automate the calculation of exposures, such as estimated daily intakes of nutrients or food groups based on food frequency questionnaires

NA = not applicable or not usually used, though not excluded.

## 3.2 Study Informativeness Assessment

Each study will be evaluated for its ability to inform the cancer hazard evaluation (informativeness) through the use of a domain-based approach (Section 3.2.1) and structured guidelines for assessing biases (that is, an evaluation of internal validity that identifies the potential for biases especially the most influential biases) and study sensitivity (the ability to detect a true effect, see Section 3.2.2 and Table 3-9). Biases in observational studies often are classified into three major categories: (1) selection bias; (2) information bias; and (3) confounding (Rothman et al. 2008). Studies should have adequate reporting methods (von Elm et al. 2007) and apply appropriate analytical methods to calculate effect estimates. Finally, studies with greater sensitivity to detect an effect (i.e., having adequate numbers of exposed cases and sufficient exposure contrasts, durations, ranges, windows of exposure, and lengths of follow-up) are considered to be more informative for the evaluation, although studies with less sensitivity may not suffer from bias per se (Cooper et al. 2016). Domain judgments (bias and study sensitivity), overall judgments of study informativeness, are made for each study (Section 3.2.3).

### 3.2.1 Domain-based Approach

Box 3-1 Bias Concern Judgments

No or minimal concern: The study characteristics being evaluated for the domain closely resemble the ideal study characteristics. The potential for bias is considered minimal, recognizing the general limitations of observational studies.

Some concern: The study design or methodologies are less than ideal for this domain. However, although the potential for bias exists, these studies are generally considered informative for the cancer hazard evaluation.

Moderate or major concern: The study design or methodologies suggest a high potential for a specific type of bias. Depending on the direction and distortion of the potential bias, the study may still be informative for cancer hazard evaluation but should be viewed with caution.

Critical concern: The distortion resulting from bias likely makes the study findings unreliable for cancer hazard identification. This category is rare.

No information: The information in the study is inadequate to evaluate the level of concern for the domain.

Direction of bias:

- ↑ Away from the null, or overestimation of the effect.
- ↓ Toward the null, or underestimation of the effect.
- Not known (unable to determine).

Magnitude of bias: Minimal, moderate or major, or unknown. In most cases, the magnitude will be unknown or subjective, but, where available, it will be based on the sensitivity analysis.

The potential for bias in each domain is captured by a core question for that domain. Core questions, together with a series of signaling and follow-up questions addressing specific issues related to the core question, are based on standard epidemiological principles (e.g., Rothman et al. 2008) and have been developed to reflect concerns that epidemiologists usually consider when evaluating studies. These concerns are also reflected in a peer-reviewed article presenting a “toolkit” that can be used to identify methodological concerns in epidemiology studies (e.g., validity, sensitivity, transparency) (Soskolne et al. 2021). The signaling questions are used to provide transparency in answering the core questions (i.e., the domain-level judgments), and a separate response is not required for each signaling question. The questions are intended to guide bias and sensitivity assessments; they are not meant to be a checklist. Although some of these concerns (such as the healthy worker effect) could be considered in more than one domain, they are evaluated in only one domain in this handbook.

To determine the potential for bias within a study, each characteristic of the actual study is compared with that of an “ideal” observational study for the study design and a specific end point and exposure, as defined in the protocol (see Section 3.1.2). However, the potential for a given bias in a study does not necessarily mean that the findings of the study should be disregarded. When there is adequate information, a judgment is made on the direction of the potential bias (whether it over- or under-estimates the effect or its direction is unknown) and the potential magnitude of the distortion caused by the bias (see Box 3-1 for guidance for bias concern judgments). (The impact of the bias on the effect estimate is discussed in Section 3.3). The overall evaluation of study informativeness is derived by integrating the domain-level judgments. In some cases, especially for exposure assessment, a study-level judgment may not be possible because of the complexity of the issues, and the evaluation will be captured by narrative text; or the categories could be expanded. An example of this was the evaluation of exposure assessment in the RoC Monograph on Trichloroethylene (NTP 2015).

Differences in reviewer rankings are resolved through mutual discussion with reference to the original data source. A small subset of studies may be used in a “pilot” phase, so that any ambiguity can be discussed and resolved before evaluation of the full set of studies. If the information to evaluate a signaling question is inadequate, the study authors may be contacted. The bias and sensitivity analyses are captured in a web-based content management system such as Table Builder. Terms used in the evaluation are defined below, and the evaluation of the specific domains follows the scheme shown in Figure 3-4.

Figure 3-4

Schematic of the Approach to Systematic Review of Study Informativeness

The bias evaluation (grey) for each domain or sensitivity (green) is captured by a core question for that domain. A series of signaling questions is used to inform the core question and domain-level judgment, including the direction, magnitude, and impact of the bias (see Section 3.3.2). To evaluate bias within a study, characteristics of the study are compared with that of an “ideal” study conditions for a specific study design, end point, and exposure. The overall informativeness assessment is based on scientific judgment considering all the domains.

### 3.2.2 Study Informativeness Evaluation Questions and Guidelines

#### Selection and Attrition Bias

Selection bias occurs when selection into the study is related to both exposure and outcome; the relationship between the exposure and outcome is different for those who participated in the study (study population) than for the source population (all those who were eligible for the study, including those who did not participate) (Rothman et al. 2008). Generalizability is determined by how representative the sample (study population) is of the target population. This is known as external validity.

Concern about selection bias is greater in case-control studies, owing to different probabilities of selection for cases and controls (Pearce et al. 2007); however, selection bias in most instances is less likely if participation was high among both cases and controls, given that the initial selection strategy was not biased.

When there is complete recruitment and follow-up, selection bias is usually less of a concern in cohort studies than in case-control studies and cross-sectional studies, because the cohort itself acts as the source population (Pearce et al. 2007); however, attrition bias or selection out of the cohort is a concern. Note that some specific biases could be considered in multiple domains. The RoC considers the healthy worker effect (HWE)—both the healthy worker-hire effect (HWHE) and healthy worker survivor effect (HWSE)—as a type of selection bias, but it can also be considered as confounding (Pearce et al. 2007). Additionally, in cancer studies, evaluation of the completeness of follow-up often overlaps with outcome determination.

Directed acyclic graphs can be used to visualize most types of selection bias, which can be described as a “collider bias,” that is, bias that results from conditioning on a common effect (the collider) of both the exposure and disease under study. For example, conditioning on the presence of cardiovascular disease (CVD) when evaluating the relationship between a genetic polymorphism that causes CVD and smoking (also a cause of CVD) would yield a distorted estimate of the exposure-outcome relationship (relative risk, odds ratio, or standardized mortality ratio) (Hernán et al. 2004). The bias can be toward or away from any true association or can cause a spurious association to appear when none exists (Hernán et al. 2004). For human mechanistic studies, other study designs may be relevant, such as cross-sectional studies, intervention studies, and randomized trials. However, the guidelines for case-control studies generally apply to those studies. Specific details will be outlined in the evaluation protocol.

For further details, see Table 3-3.

Core question: Is there concern that selection into the study (or out of the study) was related to both exposure and outcome?

Table 3-3 Selection and Attrition Bias: Questions and Guidelines

Signaling Questions | Guidance | Response Options
Selection into the study: All study designs Is there concern that the selection methods were not adequate? Did the eligibility criteria (inclusion or exclusion) or recruitment strategies differ among study participants, such as between cases and controls (case-control studies) or exposed and unexposed subjects (cohort studies)? | Participation should not be an effect of both outcome and exposure status (e.g., conditioning on a collider). Creating a directed acyclic graph may help identify colliders and whether they have been conditioned on for selection. This usually biases an estimate away from the null, but in some cases can bias it toward the null (Hernán et al. 2004). | Minimal concern There is no evidence that selection of the subjects was related to both exposure and outcome. Cases and controls or exposed and nonexposed were selected from the same source population by similar methods and criteria. For cohort studies, the cohort is clearly defined (e.g., includes groups of those exposed and unexposed for a specific time period/location, with no evidence that follow-up differs between the exposed and nonexposed). Some or major concern These are evaluation-specific and will be defined in the protocol. Critical concern There is strong evidence that selection or attrition of subjects was clearly related to both exposure and outcome.
Is there concern that study participants were not selected from the same underlying (source) population during a similar time period? | Ideally, the study participants should be similar in all respects except for exposure status (cohort) or disease status (case-control) and be drawn from the same underlying population. Note: this does not apply to population-based cohorts where the cohort is not sampled based on exposure status. For case-control studies, controls should be from the same source population as the cases and be at risk of the outcome (e.g., participants with hysterectomies should not be controls in a study of endometrial cancer). Inappropriate selection of control groups that do not represent the underlying population from which the cases are selected can be a major concern. Selection bias is less likely if there is high participation among both cases and controls given the initial strategy was not biased (Pearce and Richiardi 2014; Snoep et al. 2014). The following scenarios indicate potential bias for cohort and/or case-control studies: • Differential participation and/or response related to outcome and exposure status (cohort, case-control). • Self-selection into the study (cohort, case-control). This can be assessed by comparing participants’ characteristics with those of the general population (cohort and case-control). • Berkson’s bias (case-control). This can be largely attenuated by limiting enrollment to incident cases and further attenuated by excluding cases and controls (if controls are from a diseased group) with a co-occurring condition that is not the reason for hospitalization (Pearce and Richiardi 2014; Snoep et al. 2014). • Cohort studies: Bias can occur if both exposure and outcome change over time (dos Santos Silva 1999; Soskolne et al. 2021; Vandenbroucke et al. 2007). In cross-sectional studies, there may be concern that those with the outcome who survive long enough to participate in the study differ from those who do not survive as long or are not healthy enough to participate.
• In cohort studies, is there concern that the health of a participant may have affected selection into the study (e.g., the HWHE or healthy volunteer effect), leading to underlying differences in disease risk between exposed and unexposed individuals in the target population? • In cohort studies, is there concern that the cohort was initiated as the result of a cluster? | In occupational cohorts, standardized mortality or incidence ratios below 1 for mortality from all causes, all cancers, cardiovascular disease, or non-malignant respiratory diseases relative to the general population may be an indication of the HWE. The HWHE^a^ generally biases the findings toward the null.
Selection out of the study: Cohort study Is there concern about attrition bias or incomplete follow-up? • Is there concern that selection out of the study was related to both exposure and outcome status? • Is there concern that an analysis conditioned on censoring is related to both exposure and outcome? | Ideally, rigorous methods should be used to ascertain case status and should not differ by exposure and outcome status. Incomplete follow-up unrelated to either exposure or outcome (and therefore nondifferential) can reduce the statistical power of the study, but does not result in a biased effect estimate (Kristman et al. 2004). Loss to follow-up can occur more often for certain subgroups of the population, such as women, non-white people, and low-socioeconomic-status participants (James et al. 1997; Jewkes and Wood 1998; NCHS 2013). If this bias in vital status ascertainment is associated with exposure, this can potentially bias the study results (Linet et al. 2020). Ideally, proxy-reported deaths should be supplemented or confirmed with data from a national mortality registry to reduce loss to follow-up whenever possible (James et al. 1997). The proportion of cases using or confirmed by supplemental data should be reported.
Is there concern about the timing of follow-up (e.g., follow-up time did not coincide with the start of exposure, especially for outcomes with shorter latencies)? This may overlap with these concerns: • Prevalent hires • Left truncation • HWSE | Ideally, studies enroll participants at the start of exposure and follow them for an adequate period, which is determined by the relative latency periods for the specific type of cancer. However, start of exposure is not usually known (sometimes it is available for occupational studies), and consideration of latency period is not typical. Cohorts that consist entirely of workers identified at one point in time (i.e., including both prevalent and incident hires) have been found to over-represent long-term, healthy workers (possible HWSE) for outcomes not observable at the time of hiring (left truncation) (Applebaum et al. 2011; Picciotto et al. 2013). Although the HWSE typically biases results toward the null (Stayner et al. 2003), its magnitude can be estimated, given sufficient information on the proportions of prevalent participants or workers and the length of the follow-up period.
All studies Were analyses conducted to control for any selection bias (in or out) or sensitivity analyses conducted to address the extent of any bias? | Ideally, studies should conduct sensitivity analysis to estimate the extent of selection bias or to control for it, if methods such as these are available: • Control for (time-related) employment status (Pearce et al. 2007), such as employment duration (Garshick et al. 2012), in the analysis. • Use of statistical methods to correct for left truncation and the HWSE, such as restricting the analysis to incident hires, or use of G-estimation, inverse-probability-of-treatment methods, or censoring weights (Sterne and Tilling 2002). However, the variables needed to correct the bias are unmeasured or unavailable in most longitudinal studies. • Minimization of the HWE by conducting an internal analysis that compares the exposed workers with the unexposed workers instead of with the general population. • Calculation of the relative odds ratio (ROR) to describe the effect on nonparticipation is sometimes used (Kleinbaum et al. 1982; Nohr and Liew 2018).
If there is concern about the potential for selection or attrition bias, what is the predicted direction or distortion of the effect estimate (if there is enough information)? | When there is enough information to assess the predicted direction and/or distortion of selection or attrition bias, this assessment should be used in making the domain-level judgment for potential bias.

Hover over underlined terms for pop-up definitions.

^a^ The HWHE and HWSE are part of the healthy worker effect (HWE), which can be considered as both a type of selection bias and a type of confounding: however, it is addressed here under selection bias (Pearce et al. 2007).

#### Exposure Measurement Error and Misclassification

One of the most important aspects of an epidemiology study is its ability to correctly classify the study subjects at the individual level with respect to exposure status and level of exposure. This involves several dimensions: carefully defining the exposure used in the study, knowing sufficient information about the exposure setting (e.g., occupational, residential), selecting appropriate data collection tools and methods for using or modeling the exposure data, evaluating the quality of the exposure assessment methods, determining whether individuals can be adequately separated with respect to their exposure levels, and assessing whether knowledge of the outcome may have affected the reporting of exposure. Typically, exposure mismeasurement applies to continuous exposure data while misclassification applies to categorical (including discrete) variables.

As summarized in Section 3.1.2, a wide range of tools may be used in collecting exposure data, as well as a wide range of methods in analyzing these data. Table 3-2 shows that, depending on the type of study, certain summary measure(s) of exposure and a given method may have advantages over others with respect to potential to avoid bias. Assessing the potential for bias from measurement error (or exposure misclassification) includes consideration of: (1) how well the exposure proxy approximates the exposure of interest; (2) how accurately and precisely the exposure (or exposure proxy) is assessed (e.g., measured); and (3) differential recall bias or observational bias. Table 3-4 presents signaling questions and general considerations for assessing the risk of bias in measurement of exposure. Table 3-5 links considerations for risk of bias from Table 3-4 to the types of exposure assessments presented in Table 3-2 and the types of studies in which they are commonly used. Additional considerations are discussed below.

Any evaluation of exposure assessment includes complex consideration of the manner by which exposure data are collected, the way data are used to classify participants into exposure groups, and how missing data and datasets containing values too low to report as reliable numerical values (i.e., not detected or below the limit of quantitation) are addressed.

Biological information may also inform the evaluation of the exposure assessment. Such information, as available, can be relevant to multiple aspects of exposure assessment, including determination of whether an internal or excreted measure of exposure is most appropriate and identification of the relevant time window of exposure for a specific type of cancer (considering the relevant latency period).

Misclassification of exposure in cancer epidemiology studies is often nondifferential, which usually results in a bias toward or beyond the null (i.e., underestimation of the true risk). However, there are exceptions when non-misclassification may result in bias away from the null, such as when there is: (1) nondifferential but dependent misclassification of both exposure and outcome (e.g., self-reported exposure and outcome from the same questionnaire; however, for most cancer studies, information of cancer comes from an independent source, and this is usually not a problem) (Kristensen 1992); (2) nondifferential of multiexposure categories (however, this can attenuate or inverse the exposure-response relationship, which may bias the conclusion of the study away from the null); (3) Berkson bias results in imprecision and does not affect the magnitude of the risk estimate for linear regression models, but may bias the effect measure in log-linear models (Yland et al. 2022).

Differential bias can modify the effect estimate in any direction; in case-control studies, differential recall bias and reverse causation usually result in a bias away from the null.

Core question: Is there concern that the exposure assessment did not distinguish between exposed and nonexposed people or among exposure categories? If known, exposure assessment should be based on an etiologically relevant time window of susceptibility and exposure proxies for the cancer of interest.

Table 3-4 Exposure Measurement Bias: Questions and Responses

Signaling Questions | Guidance^a^ | Response
Exposure proxy Is there concern that the exposure proxy did not adequately represent the exposure of interest at an appropriate time window of exposure for the outcome of interest? • If yes, was this true for all exposure metrics, or a particular metric? | In observational studies, the exposure of interest is often determined through the use of an exposure proxy (e.g., measurement of a chemical metabolite, job title) and not measured directly (exposure to the substance). | Minimal concern The exposure proxy closely approximates the exposure of interest at a relevant time window for the outcome of interest. The exposure is consistently assessed through the use of established or validated methods, with minimal missing exposure data, and any measurement error is small in relation to between-individual variation compared with differences between groups. Exposure groups are adequately separated. Any misclassification is nondifferential. Some or major concern These evaluation-specific concerns will be defined in the protocol. Critical concern Exposure assessment is not at the individual level, and/or the exposure proxy does not approximate the exposure of interest well, is not within a relevant time window, or lacks other relevant metrics, resulting in poor discrimination between exposed and unexposed and among exposure groups. The number of participants with missing exposure data is large enough that the estimated effect of exposure on outcome is likely to be substantially different from an estimate generated from a complete dataset, or there are indications that the data are not missing at random.
Exposure measurement Is there concern about error in measurement of the exposure of interest or exposure proxy? Is there concern about the use of the collected data to classify exposure groups? | Any evaluation of exposure assessment methods includes consideration of how well the data are collected (see Table 3-5) and how the data are used to classify participants into exposure groups. This is particularly important for studies in which the exposure contrasts in the population are small.
If yes to either, is there concern that measurement error resulted in inadequate separation of groups with respect to exposure? • Did any misclassification vary by exposure category? • Is there concern that the exposure classification did not capture the variability of exposure? | Ideally, the exposure would be consistently assessed across exposure groups through the use of established or validated methods, with any measurement error being small in relation to between-individual variation compared with differences between groups (e.g., unexposed vs. exposed, high vs. low exposure). Consideration should be given to how a study treats samples without detectable levels of analyte. • Exposure measurement may vary depending on the timing of exposure. In studies with large proportions of exposed individuals, attention to the definition of “unexposed” is important, as these individuals may not be completely unexposed, potentially introducing bias toward the null.
• If yes to either, is the measurement error classical, Berkson, or a mixture of both? | Random misclassification of exposure may introduce bias, depending on type of error. Berkson error results in lack of precision and does not usually bias the magnitude of the effect estimate much, if at all. Classical error tends to attenuate the risk estimates (i.e., bias toward the null).
Observation and differential recall bias Is there concern that knowledge of the outcome (e.g., resulting in observation or recall bias) may potentially bias the exposure assessment (away from the null)? | Recall bias (potentially biasing toward overestimation of the effect) is not necessarily introduced when exposure information is collected after the outcome occurred. Authors may include additional data that help determine whether cases are overreporting exposures; this can help determine the likelihood of recall bias (e.g., by including an additional case group whose case status is unlikely to be related to exposure level [case-control designs] or including measures of symptoms or health outcomes unlikely to be related to exposure [cohort studies]). Differential recall bias is less likely to be a concern for self-reporting in case-control studies in which occupational exposure is assigned using participant recall of more objective data (such as job titles, occupations, work history) as a proxy for exposure than in studies using self-assessment of chemical-specific exposures or questionnaires with exposure checklists.
Has a temporal association been established—i.e., does the exposure (or proxy) measure approximate the exposure that was relevant in the time period of susceptibility? Is there concern that presence of the outcome may potentially bias the exposure assessment (e.g., reverse causality)? | Exposure or proxy measures "Reverse causality" may be a concern in retrospective or cross-sectional designs (e.g., cross-sectional studies, some case-control studies, or cohort studies with cross-sectional analysis) that measure exposure at the time of or after disease diagnosis. This can be of particular concern in studies that use biomarkers for exposure assessment.
If there is any misclassification, is it differential or nondifferential, and what is the predicted direction or distortion of the effect estimate (if there is adequate information)? | In general, nondifferential misclassification biasing toward the null occurs if there is equal exposure misclassification of cases and controls or of exposed and unexposed subjects. With more than two exposure categories, the direction of the bias is not always clear, but it may result in attenuation of the exposure-response relationship. When misclassification of exposure is not equal between cases vs. controls or exposed vs. unexposed, it is differential, and it causes a bias either toward or away from the null, depending on the proportions of subjects misclassified. When there is enough information to assess the predicted direction and/or distortion of exposure misclassification, this assessment should be used in making the domain-level judgment for potential bias.

Hover over underlined terms for pop-up definitions.

^a^ See Table 3-5 for guidance specific to different types of exposure assessments.

Table 3-5 Guidance on Exposure Assessment Methods that Reduce Various Types of Bias

Exposure Measure | Exposure Proxy | Exposure Measurements (Usually Nondifferential Misclassification) | Observational and Differential Recall Bias
Data Collection Methods
Self-report | Use an exposure proxy that is representative of the exposure of interest in the appropriate time window and one that can be reported with minimal bias. | Link exposure questions to events or types of use to provide context for respondents and improve memory; exposure details for distant past events are more difficult to remember. Ask for detailed information on calendar time, location, duration, and frequency, with multiple prompts and visual aids (e.g., portion sizes, timelines) to help subjects remember; this provides more useful information for reliably classifying participants into different exposure groups. Use structured in-person or telephone interviews. Mail or web questionnaires can be preferable when asking about sensitive topics. Query study participants (actual cases and controls), rather than proxy respondents. | Differential recall bias: • Generating exposure information prior to the outcome (i.e., in a prospective study) eliminates the potential for differential recall bias, as exposure recall may be affected by knowledge of the outcome. • Differential recall bias is less of a concern in studies asking for more objective information, such as job title, than for personal estimates of specific exposures. Observer bias: • Reduced when participants are blinded to study objectives and asked information on other exposures in addition to the exposure of interest. • Reduced when interviewers/assessors are blinded to disease (case-control) or exposure (cohort) status; this is often difficult to do in case-control studies.
Records | Use record data that have additional exposure information, as job titles alone may or may not be representative of actual exposures across locations or industries. | Use detailed records; for example, information on tasks is more informative than job titles. Use records specific to the study population (e.g., company records) rather than routinely collected data (e.g., census). | Differential recall bias: • Not relevant. Observer bias: • Most studies blind exposure assessors to case status, so this is not usually a major concern.
Environmental Measurements | Use an indicator of exposure directly measured in environmental media (e.g., air, soil, dust, or water) and specific to the timing of exposure and the population. | Individual vs. area or aggregate measurements: • Use individual-level environmental measurements, if possible, instead of area measurements for ambient levels of pollutant in outdoor air, indoor air, workplace, water, soil, or household dust. • Avoid using aggregated measures of exposure, as they are subject to considerable error for individuals, for both ever-exposure and the exposure categories used for evaluating exposure-response relationships. Sampling: • Use appropriate sampling methods and strategies that are consistently applied, following guidelines and standards. • Select sampling location(s) at random and define the number of samples, with a maximum accepted level of error. | Differential recall bias: • Not relevant. Observer bias: • Most studies blind exposure assessors to case status, so this is not usually a major concern.
Biomonitoring | Use an indicator of exposure directly measured in biological media (e.g., urine, plasma, fat, or soft tissue) that is a valid indicator of the exposure of interest, and specific to the timing of exposure population, and current biological understanding. Caution the use of biomarkers with short half-lives in studies of disease with long disease latency unless there is evidence of chronic, consistent exposure (e.g., longitudinal sampling) or relevant toxicological information. Avoid the use of nonselective markers that can be markers for other compounds (e.g., with shared metabolites). | Sampling: • Use appropriate sampling methods and strategies that are consistently applied, following guidelines and standards. Laboratory test methods: • Use high-sensitivity and -specificity methods to detect biomarkers in appropriate biological media (e.g., urine, plasma, fat, or soft tissue). • Use assays with adequate limits of detection and quantification. • Consider factors that can alter concentrations of a metabolite as a result of individual variation, and, if necessary, adjust for them or consider them as effect modifiers. | Differential recall bias: • Not relevant. Observer bias: • Most studies blind exposure assessors to case status, so this is not usually a major concern Reverse causation may be a problem in case-control or cross-sectional studies if the levels of the biomarkers are affected by the disease process.
Methods Used to Assess Collected Data
Expert Assessment or Job-exposure Matrix | Use exposure inputs for the JEM (job records and questionnaire data linking occupational exposures) or expert assessments that are representative of actual exposures either within specific locations or industries or across locations and industries. | • In general, JEMs or expert assessments applied to industrial cohorts are preferred over methods based on data from population-based or case-control studies. Assessment by experts (such as industrial hygienists or occupational physicians) is usually the most credible method for assessing occupational exposures in population-based case-control studies, as experts consider local differences in material usage, production processes, and control measures. JEMs: • Use data specific to the task, calendar year, location, and population to reflect variability in exposures within jobs from factory to factory and worker to worker. • Use multiple exposure metrics (e.g., cumulative, peak, frequency, or average intensity of exposure per unit time) that capture various dimensions of exposure, to increase the quality of the exposure assessment and increase the ability of the study to distinguish exposure groups from one another. • General population JEMs: Base algorithms on expert understanding of, and experience with, exposures in the population overall, independent of any specific subgroups. • Population-specific JEMs should include information on local conditions. Expert assessment: • Standardize assessments by independent experts across different settings in multicenter studies. In single-center studies, uniform assignment of exposure is usually not problematic, as assessment is done by only one expert or a group of closely associated experts. Misclassification of exposure levels by experts can differ greatly between the assessed exposures of interest; interrater agreement does not necessarily imply that assigned exposure levels are more accurate. | Differential recall bias: • Not relevant Observer bias: • Assessors are blinded to case status.
Modeling | Use an appropriate conceptual model in which the (causal) relationships between the model parameters and the outcome are real, and the natures (or shapes) of these relationships are known. The study documents the rationale for the model. | Use the highest-quality input data, and parameters that are accurate and appropriate for the problem. Use exposure modeling grounded in measured data and biological understanding. Use correct assumptions and parameterization. Conduct sensitivity analyses given the uncertainty associated with modeled exposure data. Demonstrate that in a specific application, the model output agrees with measured data. When possible, use continuous measures of exposure rather than categories of exposure. Categorization of a continuous variable reduces the statistical power and may negatively bias the exposure-response relationship. | Less susceptible to observer and differential recall bias.

#### Outcome Misclassification

The outcome of interest is incidence of a specific cancer type or subtype. Assessment of the potential for bias due to measurement error or outcome misclassification considers: (1) how well the study outcome represents the outcome of interest; (2) the accuracy of the outcome measurement methods; and (3) the potential for observation bias. The adequacy of follow-up length is usually evaluated in the assessment of study sensitivity. Cancer incidence data are considered more informative than mortality data, because sources of incidence data (e.g., cancer registries, hospital records) are more accurate than sources of mortality data (e.g., death certificates) (Jewkes and Wood 1998; Linet et al. 2020; NCHS 2013; Patel et al. 2004) and mortality may not reflect incidence for cancers with high survival rates.

Table 3-6 provides signaling and follow-up questions, as well as general considerations, for assessing the potential for bias due to outcome misclassification.

Core question: Is there concern that the outcome measure did not reliably distinguish between the presence or absence (or degrees of severity) of the outcome?

Table 3-6 Outcome Misclassification: Questions and Responses

Signaling Question | Guidance | Response Options
Is there concern that the method of measuring the outcome did not represent the outcome of interest? • If mortality data were used, did they adequately reflect incidence? | Ideally, each study will measure cancer incidence. Mortality data selectively miss cases with longer survival. Mortality data are adequate for types of cancer with low survival rates and may be preferable for rapidly fatal diseases, when date of death approximates date of diagnosis (i.e., incidence), or in low-to-middle-income countries that lack cancer registries or have inadequate reporting systems (so that reporting rates do not reflect the true incidence of disease) (Siddiqui and Zafar 2018; Torre et al. 2016). | Minimal or some concern Outcome measurement methods clearly distinguish between diseased and nondiseased subjects. Follow-up and diagnoses are conducted independent of exposure status. Some or major concern These are evaluation-specific and will be defined in the protocol. Critical concern There is strong evidence that the outcome measurement methods do not discriminate between diseased and nondiseased subjects and/or that follow-up and diagnoses are likely related to exposure status.
Is there concern that the disease was not accurately diagnosed? • Does misclassification of outcome vary across exposure groups or levels of exposure? • If so, were any methods used to adjust for potential bias? • Is there concern that the non-diseased group may have had the disease of interest or that the diseased group may not have? | Ideally, cases of cancer should be histologically confirmed and obtained from population-based cancer registries (PBCR). Cancer incidence data obtained from PBCR are considered the gold standard, as they consolidate data from many sources and strive to provide a complete, unbiased estimate of cancer incidence in the population. In the absence of PBCR data, incidence data can be obtained from medical records and hospital pathology data. In the United States, incidence is obtained by linking to SEER databases and may be missed if cases occur in a region not covered by SEER (which covers ~48% of the population). Additionally, the North American Association of Central Cancer Registries (NAACR (https://www.naaccr.org/)) combines data from different cancer registries in North America and can include populations not covered by SEER. If some cases are confirmed clinically or with imaging alone, the proportion of such cases should be noted. In some circumstances (e.g., difficult-to-diagnose cancer types or multicenter studies), it is preferable that at least a subset of cases undergo independent pathology review by a study investigator. There may also be inaccuracies in reporting cause of death (Flanders 1992). For cancer mortality, cause of death data from databases/registries that use algorithmic processing to standardize outcomes, such as the U.S. National Death Index, may be more reliable than death certificate data. Self-reported and proxy-reported incidence and cause of death are the least accurate sources, with proxy-reported being less accurate than self-reported. Any changes over time in subtype classification (e.g., of non-Hodgkin lymphoma subtypes and other lymphohematopoietic cancer) or deviation from specificity of the subtype of interest (e.g., leukemia vs. myeloid leukemia) should be noted, as this misclassification may dilute (reduce) effect estimates. Generally, if the number of cases is sufficient, subtypes with differing etiologies should be evaluated separately. However, in some contexts, a combined cancer type may be preferable.
Is there concern about detection bias? | Ideally, observation for cancer incidence (e.g., screening or better health follow-up) should be similar for all subgroups in the study population, but particularly for exposed and unexposed participants. Mortality data can be used to examine detection bias for some, but not all, cancers. Cancers of concern for detection bias may be female breast, thyroid, or prostate cancers (Marjerrison et al. 2022).
Is there concern about observer bias? | Ideally, the outcome assessors do not have knowledge of the subjects’ exposure status and are not influenced by exposure status. In general, cancer diagnosis is made objectively (e.g., by histopathology) and without knowledge of specific exposures (with the possible exception of smoking), so observer bias is relatively unlikely to be a concern for most cancer studies. Observer bias may be more likely for outcomes that are self-reported or reported by next of kin.
If there is misclassification, is it differential or nondifferential, and what is the predicted direction or distortion of the effect estimate (if there is adequate information)? | Nondifferential misclassification of cancer (not related to exposure status) would most likely bias the effect estimate toward the null; however, there are some exceptions (see text above). Misclassification that is differential with respect to sociodemographic characteristics (income, race/ethnicity, gender, or age) may occur for self-reported cancers (D’Aloisio et al. 2017), and the possibility that these characteristics also are associated with exposure should be considered. When there is enough information to assess the predicted direction and/or distortion of outcome misclassification, this assessment should be used in making the domain-level judgment for potential bias.

Hover over underlined terms for pop-up definitions.

#### Potential for Confounding

Confounders are factors that are moderately to strongly associated with both exposure and the disease outcome(s) of interest, as described in Protocol Development (Section 3.1.2). In lieu of randomization, the potential for confounding in observational studies can be controlled in the design phase or in the analysis phase. One option in the design phase is restriction—limiting the study to only those subjects for whom potential confounders fall within a narrow range of values (e.g., enrolling only males into a study). Another method of confounder control in the design phase is to match cases and controls by similar characteristics. In the analysis phase, confounding can be controlled through statistical techniques such as stratification and multivariable methods.

The ability to control for any confounding factor is predicated on that factor being accurately measured and quantified in the study. Assessment of the quality of measurement of exposure to the confounding factor is similar to that for measurement of the exposure of interest.

It is important to characterize the extent and impact of residual confounding (uncontrolled potential confounders), which, in turn, affects the magnitude and direction of the effect estimates. In some cases, adjusting for a factor that is not a confounder can also bias the risk estimate (i.e., if the variable is in the causal pathway). In other cases, overadjustment in statistical models for additional factors not considered to be true confounders may lower the precision of the estimates (widening the confidence intervals), but this is not likely to bias the magnitude (as discussed below, under the Analysis section).

Identifying key factors that could potentially confound the exposure-outcome relationship is a critical step in evaluating confounding bias. Our approach to this domain is twofold: first, we assess whether the studies adequately addressed the potential for confounding bias in a study, as seen in the questions below (Table 3-7). Subsequently, we assess the impact of potential confounding on the effect estimate within a study (detailed in Section 3.3.1.). In the process of considering potential confounders, particular emphasis is given to the “confounder matrix” [adapted from (Shapiro et al. 2018), as illustrated in Section 3.3.1]. The confounder matrix allows for each potential confounder to be identified, based on the protocol, and summarizes whether the confounder was addressed in the analysis, whether it was a co-exposure associated with the exposure of interest, the magnitude and direction of the association, and additional pertinent information. As detailed in Section 3.3.1, we then use the “confounder matrix” to determine whether confounding within a study can be ruled out based on scientific judgment. Potential confounders can be compared both within and across studies.

Note that the HWE can be considered as both a type of selection bias and a type of confounding (Pearce et al. 2007). For our purposes, it is addressed only under Selection and Attrition Bias (above).

Table 3-7 provides signaling and follow-up questions, as well as general considerations, for assessing the potential for bias due to confounding.

Core question: Is there concern that the effect estimate may be confounded, e.g., potential confounding is either not adequately addressed by the methods or there is inadequate information to allow for its evaluation?^a^

Table 3-7 Potential Confounding: Questions and Responses

Signaling Questions | Guidance | Response Options
Is there concern about the measurement of co-exposures or personal behaviors in the study? If no data are provided about confounders, are surrogate data on potential confounders available? | Ideally, quantitative information on personal behaviors and other likely confounders should be assessed by in-person interview conducted by interviewers blinded to the case status of the respondent, rather than via proxy respondents. Residual confounding is more likely when only limited qualitative information on a given risk factor (e.g., only “yes/no”) is available. Studies should provide data on the distribution of potential confounders by exposure and disease status. Data may be available on potential confounders in subsamples, which can help provide interpretation of the prevalence of the potential confounders in the exposed and unexposed or cases and controls. In addition, data on diseases associated with exposure may provide indirect information about risk factors for specific cancer end points of concern. | Minimal or some concern The study measured key potential confounders and/or used appropriate analyses or designs to address them. Some or major concern These are evaluation-specific and will be defined in the protocol. Critical concern There is strong evidence that the effects of the exposure cannot be distinguished from the effects of potential confounders.
Is there concern that the design or analysis did not adequately address important confounding through matching, stratification, multivariable analysis, or other approaches? • Is there additional information available with which to evaluate potential confounding or conduct sensitivity analyses (indirect adjustment)? • Is there concern that controlling for one or more variables (such as those in the causal pathway) could cause bias? • Is there concern that not adjusting for one or more confounders would be expected to differentially favor outcomes in those with higher or lower levels of exposure? | Ideally, confounders should be controlled for in the design or analysis phase. Not controlling for unaccounted potential confounders is likely to bias the results. If there is no information on confounders, determine whether external information (e.g., smoking rates in population, strength of the risk factor for the outcome) can inform whether confounding is an issue. Comparing minimally adjusted (e.g., by age) to fully adjusted models can help inform whether a factor is a confounder. Some potential confounders could be effect modifiers. Ideally, studies should stratify by these variables to indicate whether a variable is an effect modifier. Considering a variable only as a confounder may obscure possible effects in high-risk or vulnerable subgroup(s) within the study population. Statistical models over-adjusted for factors that do not meet the definition of a confounder may introduce bias. If collinearity from highly correlated co-exposures is likely to introduce confounding, determine whether additional analyses (e.g., correlation matrices, stratified models, multipollutant models, mixtures methods) can identify the individual effects while controlling for co-exposures.
What is the predicted direction or distortion of the effect estimate (if there is adequate information)? | Confounding can lead to an over- or underestimation of the risk estimate. When there is enough information to assess the predicted direction and/or distortion of confounding, this assessment should be used in making the domain-level judgment for potential bias.

^a^ The healthy worker effect is both a special type of confounding and a type of selection bias (see Selection and Attrition Bias section).

#### Analysis

The assessment of analysis bias considers the appropriateness of data assumptions, statistical models and methods used in the statistical analysis to evaluate the overall findings. Bias can occur when adjusting for variables in the causal pathway between exposure and disease. Overadjustment refers to adjusting for additional variables in statistical models that are not considered to be true confounders (see Confounding section). This would decrease precision but does not bias the results.

When adequate data are available, studies should evaluate exposure-response relationships, periods of susceptibility, and latency, or conduct subgroup analyses (especially for subgroups exposed at higher levels for longer durations). This assessment overlaps somewhat with study sensitivity. In some studies, such as case-control studies evaluating exposure to numerous substances without clear hypotheses, appropriate consideration should be given when interpreting multiple comparisons. Note: The signaling questions and guidance in the Table below are common considerations (not an exhaustive list) of the analytical considerations that may arise in epidemiological studies. Working with a biostatistician may help elucidate any biases arising from data analysis and should be further detailed in the development of a protocol.

Core question: Is there concern that the data assumptions and analysis were not adequate or that the study did not conduct relevant analysis of the available data?

Table 3-8 Analysis: Questions and Guidelines

Signaling Questions | Guidance | Response Options
Data assumptions Is there concern about whether the data assumptions used in the statistical analysis were adequate? | For example, are data transformation methods (e.g., log transformation) appropriate Or is an assumption of linearity appropriate? Were outliers removed? (Ideally, outliers should not be removed without strong justification, as that may be where the effect is strongest.) | Minimal or some concern The study used relevant data and appropriate assumptions and analysis methods. Some or major concern These are evaluation-specific and will be defined in the protocol Major or critical concern There is strong evidence that the study’s analytical methods were so limited that the findings were uninterpretable or were distorted such that no conclusion can be made.
Statistical model and methods Is there concern about the appropriateness of the statistical model for the study design or about the adequacy of the conduct of the analysis | Examples of models include Cox proportional hazards regression (hazard ratio), Poisson regression, multivariable logistic regression (odds ratio), and conditional logistic regression. Matching should be adequately described and accounted for in the analysis (e.g., for controls described as individually matched to cases, was the ratio of cases to controls included, and were conditional regression techniques applied?).
If applicable, did the study use appropriate methods to adequately evaluate exposure-response and latency, or to conduct subgroup analyses? | Analyses of subgroups exposed at higher levels or for longer durations should use appropriate methods to delineate groupings. Questions about the adequacy of methods include whether the data were modeled continuously or divided into categories, and whether the analysis used linear tests for trend and appropriately stratified groups.
Is there concern about “over-controlling” (i.e., controlling for variables unnecessarily)? | Controlling for variables that are not related to exposure or disease will most likely reduce the precision of the risk estimate.
Missing data Is there concern that missing data may have biased the findings? • Is there concern that missing data on the outcome or on any potential confounders is substantial? • Is there concern that missing data were not handled by an analytically appropriate method (e.g., sensitivity analysis or imputation)? | Complete subject analysis (i.e., including only those participants with complete data for all variables modeled) is considered less than ideal. Ideally, there should be little or no concern that the data are missing for reasons related to both exposure and disease.
What is the direction, magnitude, and impact of this bias on the effect estimate? | When there is enough information to assess the predicted direction and/or distortion of analysis bias, this assessment should be used in making the domain-level judgment for potential bias. This may be difficult to ascertain for most analyses.

#### Study Sensitivity

Study sensitivity is the ability of a study to detect a true effect (Cooper et al. 2016) and is analogous to the term “informativeness” as used in the preamble to the IARC Monographs (IARC 2019; Samet et al. 2020). (Both IARC and RoC evaluate bias and sensitivity but used different terminology to describe study sensitivity). Studies that have a low risk of bias but are insensitive may not be informative for reaching public health decisions about a potential causal relationship between exposure and outcome, as they are less likely to be able to detect a true effect even if one exists. Both sensitivity and the potential for bias must be considered in order to identify the most informative studies and to identify those study elements that may help to explain heterogeneity across the body of literature. Failure to consider sensitivity may result in overweighting the results from insensitive studies or erroneously interpreting evidence as being conﬂicting (Cooper et al. 2016). Study sensitivity should be evaluated with the same rigor as bias assessment.

Assessment of study sensitivity includes consideration of: (1) study size or the numbers of exposed and unexposed participants or cases and controls; (2) exposure contrast and window; and (3) follow-up times based on estimated minimum latency period for the exposure and outcome of interest. The overall sensitivity evaluation requires integration of these factors. For example, a study evaluating effects from low levels of exposure most likely will need larger numbers of exposed subjects than studies of subjects exposed at higher levels. Table 3-9 provides signaling and follow-up questions pertinent to these issues and to general considerations for assessing study sensitivity.

In some cases, the line between biases and study sensitivity is not clear. Some systematic review methods consider questions in the study sensitivity domain that RoC considers in the bias assessment domain, such as: (1) the relationship between the participant’s entry into the cohort and onset of exposure in the selection-bias domain;(2) the appropriateness of the exposure or outcome measure to the exposure or outcome of interest in the information-bias domain; and (3) the use of models inappropriately including factors that are not confounders in the analysis domain. Care should be taken to avoid considering the same issue in more than one domain.

Core question: Does the study have adequate sensitivity to detect an effect from exposure (if present)?

Table 3-9 Study Sensitivity: Questions and Guidelines

Signaling Questions | Guidance | Response Options
Statistical power Is there concern that the numbers of exposed cases were not adequate for detection of an effect in the exposed population or subgroups of the exposed population? | When both exposure and disease are rare, statistical power is determined largely by the number of exposed cases and exposed controls. | No or minimal concern The study had an adequate number of exposed subjects, with substantial exposure (level, duration, or range) and with adequate duration of follow-up for latency status. Some or major concern These are evaluation-specific and will be defined in the protocol Critical or major concern The study was modest or small, with few exposed subjects, and/or the exposure range was minimal.
Exposure contrast Is there concern that the levels, duration, or range of exposure of the population at risk in cohort and case-control studies was not sufficient or adequate for detection of an effect of exposure? • Did the exposed group include individuals with a low or unknown probability of exposure? | Dilution of risk estimates comparing exposed and referent groups can occur when exposure varies widely within the group(s) deﬁned as exposed. Alternatively, in communities where a large proportion of subjects are exposed, those who are defined as “unexposed” may in fact be exposed, making it difficult to detect a signal. The ability to evaluate exposure-response relationships depends on an adequate range of exposure among the study participants and adequate numbers of participants in each exposure category.
Is there concern that the exposure assessment did not capture the relevant exposure metric, ideally to the outcome of interest (if biological understanding is known)? | The relevance of the exposure metric could be considered in exposure misclassification instead of study sensitivity, which would be delineated in the substance evaluation protocol.
Latency Was the elapsed time between exposure and the outcome measurement sufficient to allow for cancer induction? | The follow-up period should be relatively long, as cancers typically have latency periods ranging from years to decades. In addition, the age of the cohort should be considered. Assessment of relevant time windows of exposure, or use of analytic models that are lagged, consistent with knowledge of the latency of a specific type of cancer or other experimental data, are recommended, as the strength of the association between exposure and cancer risk may be stronger when capturing relevant exposure windows (Checkoway et al. 2019). Ideally, estimates of the minimum estimated time from initiation to cancer (i.e., minimum latency) from the exposure are based on direct observation of latencies.

### 3.2.3 Overall Assessment of the Study

Box 3-2 Study Informativeness-Level Judgement

High: no or minimal concerns about most potential biases, high or moderate sensitivity.

Moderate: low, minimal, or some concerns about most potential biases.

Low: major concerns about several biases, sensitivity rating varies. Depending on the direction and distortion of the potential biases, the study may still be informative for the cancer hazard evaluation and can help explain heterogeneity of the findings.

Inadequate (very rare): critical concern about any bias; sensitivity rating varies.

The overall informativeness of a study is based on consideration of both the potential for bias (i.e., internal validity) and study sensitivity. Serious concerns about study quality will result in a lower informativeness judgment. However, a well-designed study with low sensitivity (e.g., having few exposed or expected cases for a specific end point) could be considered as having low informativeness for the cancer hazard assessment. In very rare cases, a study that meets inclusion criteria may ultimately be excluded from evidence integration if they are totally and obviously uninformative (such as documented evidence of severe exposure misclassification). For transparency, the study informativeness assessments are included in the monograph, and the findings may be briefly summarized, or evaluated in sensitivity analysis. Past example from the night shift work evaluation include a study using a JEM that predicted that only 0.06 of the participants were night shift workers in a country with a predicted estimate of 10% to 20% female night shift workers (Schwartzbaum et al. 2007). In the IARC Monograph evaluation of coffee and bladder cancer (IARC 2018), the working group focused its review on studies that adjusted for tobacco smoking (a strong risk factor and confounder), and studies that did not adjust for smoking were not carried forward for full review, because of the resource constraints associated with reviewing a large number of studies with limited informativeness. When adequate information is available for a study, a judgment is made on the direction and distortion of its overall biases or whether it has low sensitivity to detect an effect (see Box 3-2).

The goal of the evaluation is to consider all the evidence and triangulate across the body of evidence, rather than exclude studies. Studies raising critical concern about bias (which is very rare) in at least one domain may be evaluated in the sensitivity analysis. The overall judgment of study informativeness is not meant to be an algorithm that sums up the ratings across domains. Different domains may be given greater weight depending on issues important for the specific candidate substance. For databases in which the quality of the studies varies considerably, informativeness-level categories may be combined, such as “moderate or low” (e.g., as in the case of trichloroethylene).

## 3.3 Evidence Evaluation and Integration

Following the assessment of study informativeness, evidence from individual studies is evaluated (Section 3.3.1) and integrated across studies (Section 3.3.2) to reach a level-of-evidence conclusion (sufficient, limited, or inadequate) about the carcinogenicity of the substance from studies in humans by applying the RoC criteria (see Box 3-3) to the assessment. The assessment is made for each cancer outcome, and the overall conclusion is based on the highest level of evidence (i.e., if the level of evidence for one cancer type is sufficient, the overall level of evidence is considered sufficient; levels of evidence for the other cancer types are noted). The evidence from the human cancer studies is integrated with the evidence from animal cancer experimental studies and mechanistic studies to reach the listing recommendation. Applying the RoC listing criteria to the body of studies on a specific substance involves evaluating: (1) whether there is credible evidence for an association between exposure to the substance and cancer and (2) whether such an observed association can be reasonably explained by chance, bias, or confounding.

Box 3-3 Report on Carcinogens Listing Criteria for Evaluating Carcinogenicity from Studies in Humans

Sufficient evidence of carcinogenicity from studies in humans: a causal relationship between exposure to the agent, substance, or mixture and human cancer.

Limited evidence of carcinogenicity from studies in humans: a causal interpretation is credible, but alternative explanations, such as chance, bias, or confounding factors, could not adequately be excluded.

The cancer hazard evaluation builds upon the assessment of study informativeness and assesses confidence in the findings from individual studies, which includes evaluating the impact of bias on the studies’ findings (considering the magnitude and direction of the bias and the strength of the findings) (Section 3.3.1). The bias judgments (overall study judgment, domain judgment, and specific biases), effect modifiers, exposure metric, and other scientific issues are systematically explored across studies to evaluate consistency and potential sources of heterogeneity (Section 3.3.2). Finally, triangulation approaches and consideration of other causality factors (e.g., Bradford Hill considerations, causal inference) also guide the assessment, giving weight to the most informative studies and considering all the evidence (Section 3.3.2).

### 3.3.1 Evidence Evaluation

Conclusions regarding confidence in a given study are reached by evaluating the impact of specific potential biases and considering the strength and consistency of the findings. Information from other studies may also inform the evaluation of individual studies.

#### Evaluating the Impact of Bias on the Study Findings

The presence of potential bias (such as selection bias or information bias due to misclassification of exposure or outcome) or confounding does not necessarily mean that a study should be excluded from the hazard assessment. Conclusions about the evidence from each study should consider the strengths and weaknesses of that study, the direction and distortion of the biases, and the strength of the association between exposure to the substance and the specific type of cancer.

Lash et al. (2014) and others have proposed practices for quantitative bias analysis to estimate the direction, magnitude, and uncertainty of systematic bias. However, many but not all methods require the individual study data, which rarely are available for published studies. Nonetheless, there is growing interest in evaluating the impact of bias in published studies, and new methods may therefore be incorporated as these methods are advanced (IARC 2024). Most methods and approaches that have been developed focus on confounding, but some concepts could apply to other types of bias (e.g., from exposure misclassification). In addition, evaluations of recall bias and selection bias have been reported. However, the information needed to evaluate these types of bias (such as on nonparticipants) often is not available.

##### Confounding

The strength of the association can be important in evaluating whether specific confounders or biases can explain the observed association between exposure and cancer. When the magnitude is large, the effects of potential confounding (known, residual, or unknown) or bias typically are minor (Blair et al. 2007). However, in judging the magnitude of the risk estimate, the direction and distortion of the bias or confounding must be considered. For example, there may be data (e.g., sampling) to suggest that potential confounding from smoking could explain only 10% of an increase in cancer; therefore, one could have confidence in a study reporting an effect estimate of a relatively low but larger than 10% magnitude. Evidence that risk increases with increasing levels of exposure can help rule out bias, confounding, and chance with reasonable confidence and can provide convincing evidence of a credible association between exposure and disease. This is important for both identified confounders and unknown confounders.

RoC considers several qualitative and quantitative approaches for evaluating residual and unmeasured confounding at both the individual study level and across studies. It may also be possible to conduct sensitivity analyses (indirect adjustment) to evaluate the direction and extent of the potential confounding. This usually requires that the magnitude of the effect estimate for the confounder and disease be known and that information is available to estimate the prevalence of the confounder among the exposed and comparison groups (Pearce et al. 2007).

Axelson and Steenland (1988) proposed indirect methods (e.g., the following formula) for evaluating potential confounding from tobacco use when little or no smoking data are available. This method can be applied to other confounders. Using the value obtained for I0, the risk ratio due to the confounder can be estimated for various hypothetical populations with different proportions of the confounders (Box 3-4).

Box 3-4 Axelson and Steenland Formula for Bias Adjustment

I = RI_0_ P_CF_ + I_0_(1 - P_CF_)

I = incidence of the disease in the population

I_0_ = rate of disease in non-smokers (i.e., without the confounder)

R = risk ratio of the confounder

P_CF_ = proportion of the population with the confounder

Another approach is to calculate the E-value, which VanderWeele and Ding (2017) define as the minimum strength of association that an unmeasured confounder would need to have with both the exposure and the outcome to fully explain the exposure-outcome association. The larger the E-value, the greater the unmeasured confounding would need to be in order to explain the risk estimate. A major limitation of this approach is that it assumes that the prevalence of the uncontrolled confounder among the exposed is 100%, which is highly unlikely and limits the utility of this approach (MacLehose et al. 2021). An online calculator is available for calculating e-values (https://www.evalue-calculator.com/).

The RoC process uses a confounder matrix [as shown in Figure 3-5, below, adapted from Shapiro et al. (2018)], which can incorporate the quantitative approaches discussed above or qualitative considerations for considering potential confounders. The confounder matrix allows for each potential key confounder to be identified based on the protocol and indicates whether the confounder was addressed in the analysis, whether the confounder was a co-exposure associated with the exposure of interest and the strength of the association is known, the magnitude and direction of the association, additional pertinent information, and whether confounding within a study can be ruled out based on scientific judgment. Potential confounders can be compared both within and across studies. Importantly, the confounder matrix is not a checklist but a tool to assist with determining the impact of confounding bias on an individual study’s findings and across studies.

Figure 3-5

Confounder Analysis Matrix (Shapiro et al. 2018).

The summary table allows users to identify and view potential confounders in a matrix format and evaluate whether handling of these potential confounders can explain the findings within and across studies. This example displays studies examining the association between exposure to antimony and lung cancer mortality. Below the summary table, pertinent information on potential confounders from each study is extracted and evaluated.

##### Other Biases

The magnitude of the impact varies by the degree of misclassification and prevalence of the exposure. Sensitivity analyses can be performed to estimate the theoretical impact of exposure misclassification on risk estimates with data on the validity of exposure measurements (e.g., sensitivity and specificity) and predicted relative risks (Checkoway et al. 2004; Columbia Mailman School of Public Health 2024; Rothman et al. 2008). This information is rare, but assumptions can be made. Publications describing this theoretical exercise have demonstrated that relatively small errors (10% to 20%) can have large impacts on risk estimates (Copeland et al. 1977; Flegal et al. 1986). The potential for differential exposure misclassification can be inherent to case-control studies (e.g., due to recall bias or reverse causation), but the impact is generally thought to be minimal (Blair et al. 2007).

Methods have been developed to examine the effects of both selection and recall bias in case-control studies. For example, two large case-control studies on mobile phone use and cancer, the INTERPHONE study (Vrijheid et al. 2006), and the CEDALO study (Aydin et al. 2011) used Monte-Carlo simulation methods to determine the impacts of these biases on the risk estimates. These analyses are rare, as they rely on additional data (e.g., information on nonrespondents or validation data), and it is uncommon for studies to have the information needed to conduct these analyses (Greenland 1996).

#### Evaluating Confidence in Individual Study Findings

Confidence in a study’s findings (i.e., evidence for or against an association) involves considering the strength of the association, the potential for specific biases or confounding, the direction and distortion of those biases or confounding (i.e., their impact on the findings), and the sensitivity of the study to detect an effect (see Box 3-5 for guidance). Study confidence is based on scientific judgment and not criteria or checklists, which is especially important for studies for which there is a major concern about a potential bias. For example, if a study finds an association between exposure and disease despite concern about bias toward the null, the findings could be considered as supporting evidence. However, if the direction of the bias is unknown or away from the null, that study would probably not be considered in the integration of the evidence across studies.

Box 3-5 Axelson and Steenland Formula for Bias Adjustment

Moderate or strong evidence of an association (increased or decreased): Integration of the following considerations including (not all required): patterns showing internal consistency, evidence of an exposure-response relationship, or presence of a statistically significant risk from a well-designed study. These studies have a limited potential for (or small distortion from) bias, or any bias that may be operating tends mainly toward the null, underestimating the risk estimate (for a positive association). Methods used to assess confounding or information available on potential confounders indicate that potential confounding is unlikely to account for all of the excess or reduced risk.

Some evidence of an association: Evidence of an association, but the strength of the association is not likely to be fully accounted for by potential confounding or bias.

Null: Effect estimates are close to 1.0, but most potential bias is toward the null, or the study has low sensitivity to detect an effect.

Inconclusive: Study findings vary, but it is unclear whether all the excess or decreased risk can be explained by potential bias or confounding, or the direction of bias is unknown.

In addition to considering the potential for biases in the context of the strength of the findings (magnitude and exposure-response relationships), confidence in a study also is based on consideration of factors such as internal consistency. Examples of internal consistency include findings that are similar in both external and internal analyses or across different metrics of exposure. However, inconsistency may be attributed to design features (e.g., such as the HWE) or biological reasons (e.g., a specific metric may be related to the mode of action of a specific substance).

Statistical significance depends on power (sample size) and is not needed to assess the role of chance in a study’s findings (Rothman et al. 2008). Rather, other factors less dependent on sample size, such as the width of the confidence interval (a narrower confidence interval indicating a more precise estimate) and consistency of patterns of findings within a study, can better be used to address the role of chance. Additionally, the conventional cutoff value for significance of p < 0.05 is somewhat arbitrary and does not have the same meaning in observational studies as it does in experimental studies (Brownstein et al. 2019; Wasserstein et al. 2019). Study power (usually gauged by the reported number of exposed cases and nondiseased) is assessed as one factor that contributes to study sensitivity, and the full range of considerations outlined above (strength of association, potential for and impact of specific biases such as confounding or selection bias, consistency across study metrics, and additional factors related to sensitivity, such as the timing of exposure measurement) determine the level of confidence in a study’s findings.

### 3.3.2 Evidence Integration Across Cancer Epidemiology Studies

The finding of consistent positive associations that are replicated across studies in different populations, with different study designs, and in different occupational settings reduces the likelihood that specific biases or potential confounders in individual studies explain the positive associations.

#### Evaluating Bias Across Studies

##### Domain or Specific Bias Analyses

In addition to analyzing biases in individual studies, evaluation of the most influential biases (e.g., nondifferential exposure misclassification) across studies is a useful step to understanding the overall impact of a specific bias on a body of literature. This includes a broader qualitative and/or quantitative understanding of the magnitude, direction, and impact of each common bias, when possible.

Each common bias may have unique aspects that should be considered. For example, if evaluation of the impact of confounding across studies found no appreciable differences between unadjusted and adjusted effect estimates, this would increase confidence in ruling out confounding from measured confounders. Relatedly, confounding by smoking may be minimized if no differences are seen between smoking-specific and nonsmoking populations.

##### Triangulation

Triangulation is an approach to evidence synthesis that requires a more inclusive view, integrating data from different methods, designs, theoretical approaches, and unrelated sources of bias to see whether the evidence suggests a single conclusion (Lawlor et al. 2016; Vandenbroucke et al. 2016). In this approach, a study would not automatically be downgraded because of bias; rather, the potential for influential biases for each study is recognized, and, if possible, the effect of that bias on the direction or magnitude of the effect estimate is identified. In a review, if different sources of bias exist across studies, but the results are consistent, given these potential biases, then this triangulation of the data can help increase the certainty of the reviewer’s conclusion (Arroyave et al. 2021; Lawlor et al. 2016). Triangulation approaches can be used in integrating the evidence across studies of a similar discipline (human cancer epidemiology studies) or across disciplines. The latter approach can help inform an evaluation of cohesiveness or biological plausibility.

#### Bradford Hill Guidance

Several additional considerations—strength of the association, consistency across studies, evidence of an exposure-response gradient, and temporality of exposure (Bradford Hill 1965)—can assist in determining whether the findings can be better accounted for by alternative explanations. However, it should be noted that that these are not criteria; with the exception of temporality, not every element is required in order to demonstrate causality (Rothman and Greenland 2005). Biological plausibility is addressed in the assessment of mechanistic data (see Section 6).

##### Consistency and accounting for sources of heterogeneity across studies

Evaluation of the consistency and sources of heterogeneity across studies are key considerations in determining whether there is a credible association between the substance and cancer incidence. The evidence from studies should be systematically evaluated in the context of study informativeness (overall and specific biases, such as type of exposure assessment or potential confounders) and other key scientific issues or factors identified during the scoping activities—e.g., study design, population characteristics (including whether disproportionally affected populations have been included), exposure metrics, latency, cancer subtypes, and effect modifiers. This analysis may help explain the heterogeneity of findings (e.g., the associations between exposure to trichloroethylene and kidney cancer were stronger in the most informative studies or in the studies that estimated the highest exposure) or help contextualize the exposure (e.g., the strongest associations of night shift work and breast cancer were for long-term and frequent night shift work). Risk estimates can be visualized by stratification (for each factor), and a heatmap can be used to visualize the analysis across forest plots [see Table 3.5 in the Night Shift Work Monograph (NTP 2021a) for an example of a heatmap for night shift work and breast cancer]. In many cases, there are limited numbers of studies to stratify by multiple factors and it may be challenging to determine whether lack of consistency (if any) is due to biases or unmeasured but real effects (such as effect modifiers). Meta-analyses and meta-regression can also be used to evaluate consistency and sources of heterogeneity.

For a level-of-evidence conclusion to be reached, a positive (or negative) association needs to be replicated in more than one study or provide internal consistency within a multicenter or multicohort study; however, the precise considerations (e.g., number of studies) cannot be established, because the degree of replication may depend on the nature of the studies and the strength of the association observed. For example, findings from multicenter or multicohort studies of different populations would have greater weight than findings from a single factory or small case-control studies. In addition, weak associations may need to be replicated in more studies than strong associations (e.g., the evidence from studies on environmental tobacco smoke comes from many studies reporting relatively modest risk estimates (~20% in the meta-analysis), whereas the evidence for ortho-toluidine comes from a few studies reporting higher risk estimates (greater than fivefold) (NTP 2021b; 2021c).

Consistency of findings across studies is a method of ruling out chance as a driver of association. Although determining whether or not the statistical significance of the findings is replicated across studies may be involved, it is important to note that statistical significance is not the primary or sole indicator of consistency across studies, and in fact is not required to show consistency of findings or evidence of an association (Brownstein et al. 2019; Wasserstein et al. 2019). A full evaluation of consistency takes into consideration the factors outlined above (e.g., replication, heterogeneity, strength of the association) to determine whether or not the various findings are compatible with a consistent underlying effect (Amrhein et al. 2019).

##### Temporality

Exposure must occur before the disease outcome. In some studies (such as case-control studies with a cross-sectional exposure assessment), mechanistic and other relevant data may be used to inform temporality (see Viruses, NTP 2021d).

##### Strength of observed associations

The strength of the association, as measured by the magnitude of the effect estimate, may be difficult to evaluate across studies (in the absence of a meta-analysis), since effect estimates are likely to vary across studies for several reasons (e.g., differences in exposure conditions, outcome measurements, or populations). Although a higher magnitude may provide greater confidence that an association is not likely due to chance, bias, or confounding, this is not required in order to demonstrate causality. There are many examples of weak associations between exposure to a substance and an end point that are nevertheless considered to be causal (e.g., environmental tobacco smoke and lung cancer).

##### Evidence for an exposure-response gradient

As with the magnitude of an association, a positive exposure-response relationship can help rule out bias, confounding, and chance with reasonable confidence, as well as provide convincing evidence of a credible association between exposure and disease, which is important for both identified confounders and unknown confounders. Dose-response curves for established carcinogens include direct monotonic, inverse monotonic, J- or U- shaped, or plateau-shaped relationships. For example, radiation has a dose-response curve that plateaus, because it kills cells at high doses. For many occupational exposures, risks are attenuated at high doses, for a variety of reasons (Stayner et al. 2003). There may be biological or methodological reasons for not observing a gradient, and the absence of evidence for an exposure-response relationship is not strong evidence per se for the absence of a causal association. If adequate information on exposure levels (or duration) is available, exposure-response relationships can be evaluated across studies, in addition to within individual studies.

#### Meta-analysis and Meta-regression

A meta-analysis is a valuable tool and may be conducted in parallel with a qualitative hazard assessment to explore heterogeneity and inform the cancer hazard evaluation. However, it may be difficult, and sometimes inappropriate, to combine study data from observational studies for meta-analysis, particularly studies in environmental and occupational health, because of differences in exposure definitions, exposure levels, and outcome. For example, in the NTP cancer assessment report on night shift work, a reviewed meta-analysis of night shift work and breast cancer was not considered informative for evaluating potential causality because of heterogeneity in the definition of night shift work (the exposure) across study populations.

Meta-analytic techniques and visualization tools showing point estimates and confidence intervals (such as forest plots) can be used to assess factors contributing to heterogeneity between studies and the potential for publication bias. It is important to define a priori the sources of heterogeneity that will be explored in a meta-analysis. Heterogeneity across studies is expected, as studies are conducted in populations that differ in geographical location, socioeconomic conditions, and exposure patterns (Higgins et al. 2009). The I^2^ statistic is the percentage of variation across studies due to heterogeneity rather than chance. However, it is not a measure of absolute heterogeneity (i.e., does not provide the predicted range of effect sizes due to heterogeneity) (Higgins and Thompson 2002; Higgins et al. 2003). The I^2^ statistic should be interpreted with expert scientific judgment. For example, hypothetically, it is possible that combining studies that report different exposure matrices but with risk estimates of similar magnitude could result in a low value for the I^2^ statistic. Thus. the studies would appear to be homogeneous but the meta-analytic estimate would be impossible to interpret as there is inherent inconsistency when combining results across different exposure matrices.

Publication bias occurs when the findings of published studies differ from those of unpublished studies; in particular, null findings may be more likely to be unpublished, whereas published studies may be more likely to report an effect. However, publication bias may be less of a concern for qualitative evaluations that rely on more informative studies. Most of the available methods for evaluating publication bias are meta-analytical techniques (such as funnel plots and “trim and fit”) that may be subject to error (Macaskill et al. 2001). Interpretation of funnel plot asymmetry (visual inspection and related analysis) can be affected by several factors including methodologic quality, statistical significance, and heterogeneity.

Some examples of quantitative meta-analyses that informed the qualitative evaluation of the evidence for a hazard assessment were analyses conducted by the U.S. Environmental Protection Agency (Scott and Jinot 2011) to assess the association between trichlorethylene and kidney cancer and the IARC Working Group’s analysis of welding fumes and lung cancer (Honaryar et al. 2019). Both meta-analyses were rigorously conducted by a panel of subject-matter experts, with an in-depth exploration of factors that contributed to heterogeneity. These meta-analyses transparently illustrate the qualitative hazard evaluations and led to evidence-based policy changes shortly following publication of the hazard assessment (Cherrie and Levy 2020; HSE 2019).

When properly conducted, meta-analysis is a valuable tool to explore heterogeneity and quantify an exposure-outcome relationship explored in a systematic review. (Quantifying biases is not an objective for hazard identification.) However, the potential for bias must be investigated with the same rigor in a meta-analysis as in the individually published studies. The proliferation of published meta-analyses in a very short time has resulted in the use of incorrectly extracted data, effect estimates from multiple studies with overlapping participant populations, combining studies using entirely different exposure metrics, and inclusion of studies that do not evaluate the end point of interest.

## 3.4 Reporting and Data Extraction

### 3.4.1 Data Extraction

Data (such as methods and results) from the individual studies are extracted into a web application (such as Table Builder, Shapiro et al. 2018) in a systematic manner using standardized instructions and questions. The database contains fields that are specific for the various types of extracted information (such as study population characteristics, exposure and outcome assessment, analytical methods, and results). The instructions for data extraction (questions and considerations) describe the specific type of information that should be summarized or entered into each field. The fields from the database are used to populate tables for the monograph.

Typically, for studies in which multiple updates or re-analyses have been published, the reviewer should extract data from the most recently published follow-up or update for each type of cancer included in the study. If there is overlap between study populations, the publication with the most complete or relevant follow-up of the study population usually is reported. Information (such as exposure data or re-analyses) from relevant publications may also be included in the review if it is needed to assess the study.

Quality assurance of data extraction and database entry are accomplished by: (1) review of the data entry by an independent reviewer and (2) resolution of any discrepancies by mutual discussion with reference to the original data source.

### 3.4.2 Reporting

Presentation of the data and key study information is crucial in a systematic review, and an important factor in understanding the impact of the conclusions. Systematic reviews generally include these elements:

- A discussion of the key scientific issues (as defined above) for the specific exposure and outcome relationship.
- An overview of study characteristics (e.g., population characteristics, exposure assessment methods, outcomes) included in the review, even if not included in the evidence integration for bias, quality, or other reasons.
- A discussion of biases and limitations for each bias domain across studies, in addition to the rationale for the risk of bias at the study level.
- A scientific narrative of the interpretation of study findings, including a discussion of the confidence in the evidence from each study, heterogeneity across studies (not limited to the potential for biases), and the rationale for the conclusion (e.g., consideration of dose-response relationships, consistency, ruling out of chance, bias, and confounding with reasonably confidence).
- Findings from studies—reported in summary tables and graphed in forest plots.
- Preliminary level-of-evidence conclusions for cancer types of interest.

An evidence-based table captures the overall assessment and is brought forward to the overall evidence integration to reach a preliminary listing recommendation (see Section 7).

Table 3-10 Template Example for Summarizing the Assessment of Key Evidence from Human Cancer Epidemiological Studies

Exposure | Outcome | Evidence Streams | Strength and Limitations | Assessment
Substance | Cancer Type | Number and type of human cancer studies Cohort studies Case-control studies Pooled or meta-analyses | Summary of most influential biases (direction, magnitude, impact) across studies by study design or other relevant grouping | Consistency of findings and patterns for factors, such as exposure matrices and levels, cancer subtypes, effect modifiers

## References

Amrhein V, Greenland S, McShane B. 2019. Scientists rise up against statistical significance. Nature. 567(7748):305–307. 10.1038/d41586-019-00857-9 30894741
Applebaum KM, Malloy EJ, Eisen EA. 2011. Left truncation, susceptibility, and bias in occupational cohort studies. Epidemiology. 22(4):599–606. 10.1097/EDE.0b013e31821d0879 21543985
Arroyave WD, Mehta SS, Guha N, Schwingl P, Taylor KW, Glenn B, Radke EG, Vilahur N, Carreón T, Nachman RM, et al. 2021. Challenges and recommendations on the conduct of systematic reviews of observational epidemiologic studies in environmental and occupational health. J Expo Sci Environ Epidemiol. 31(1):21–30. 10.1038/s41370-020-0228-0 32415298
Axelson O, Steenland K. 1988. Indirect methods of assessing the effects of tobacco use in occupational studies. Am J Ind Med. 13(1):105–118. 10.1002/ajim.4700130107 3344750
Aydin D, Feychting M, Schüz J, Andersen TV, Poulsen AH, Prochazka M, Klaeboe L, Kuehni CE, Tynes T, Röösli M. 2011. Impact of random and systematic recall errors and selection bias in case-control studies on mobile phone use and brain tumors in adolescents (CEFALO study). Bioelectromagnetics. 32(5):396–407. 10.1002/bem.20651 21294138
Blair A, Stewart P, Lubin JH, Forastiere F. 2007. Methodological issues regarding confounding and exposure misclassification in epidemiological studies of occupational exposures. Am J Ind Med. 50(3):199–207. 10.1002/ajim.20281 17096363
Bradford Hill A. 1965. The environment and disease: Association or causation? Proc R Soc Med. 58(5):295–300. 14283879
Brownstein NC, Louis TA, O’Hagan A, Pendergast J. 2019. The role of expert judgment in statistical inference and evidence-based decision-making. Am Stat. 73(1):56–68. 10.1080/00031305.2018.1529623 31057338
Checkoway H, Lees PSJ, Dell LD, Gentry PR, Mundt KA. 2019. Peak exposures in epidemiologic studies and cancer risks: Considerations for regulatory risk assessment. Risk Anal. 39(7):1441–1464. 10.1111/risa.13294 30925210
Checkoway H, Pearce NE, Kriebel D. 2004. Research methods in occupational epidemiology. 2nd ed. New York, NY: Oxford University Press. 10.1093/acprof:oso/9780195092424.001.0001
Cherrie JW, Levy L. 2020. Managing occupational exposure to welding fumes: New evidence suggests a more precautionary approach is needed. Ann Work Expo Health. 64(1):1–4. 31686108
Cocco P, Vermeulen R, Flore V, Nonne T, Campagna M, Purdue M, Blair A, Monnereau A, Orsi L, Clavel J, et al. 2013. Occupational exposure to trichloroethylene and risk of non-Hodgkin lymphoma and its major subtypes: A pooled InterLymph analysis. Occup Environ Med. 70(11):795–802. 10.1136/oemed-2013-101551 23881218
Columbia Mailman School of Public Health. 2024. Probabilistic sensitivity analysis of misclassification. New York, NY: Columbia University. [Accessed: May 9, 2024]. https://www.publichealth.columbia.edu/research/population-health-methods/probabilistic-sensitivity-analysis-misclassification
Cooper GS, Lunn RM, Ågerstrand M, Glenn BS, Kraft AD, Luke AM, Ratcliffe JM. 2016. Study sensitivity: Evaluating the ability to detect effects in systematic reviews of chemical exposures. Environ Int. 92-93:605–610. 10.1016/j.envint.2016.03.017 27156196
Copeland KT, Checkoway H, McMichael AJ, Holbrook RH. 1977. Bias due to misclassification in the estimation of relative risk. Am J Epidemiol. 105(5):488–495. 10.1093/oxfordjournals.aje.a112408 871121
D’Aloisio AA, Nichols HB, Hodgson ME, Deming-Halverson SL, Sandler DP. 2017. Validity of self-reported breast cancer characteristics in a nationwide cohort of women with a family history of breast cancer. BMC Cancer. 17(1):692. 10.1186/s12885-017-3686-6 29058598
dos Santos Silva I. 1999. Cancer epidemiology: Principles and methods. Lyon, France: International Agency for Research on Cancer. https://publications.iarc.fr/Non-Series-Publications/Other-Non-Series-Publications/Cancer-Epidemiology-Principles-And-Methods-1999
Flanders WD. 1992. Inaccuracies of death certificate information. Epidemiology. 3(1):3–5. 10.1097/00001648-199201000-00002 1554807
Flegal KM, Brownie C, Haas JD. 1986. The effects of exposure misclassification on estimates of relative risk. Am J Epidemiol. 123(4):736–751. 10.1093/oxfordjournals.aje.a114294 3953551
Garshick E, Laden F, Hart JE, Davis ME, Eisen EA, Smith TJ. 2012. Lung cancer and elemental carbon exposure in trucking industry workers. Environ Health Perspect. 120(9):1301–1306. 10.1289/ehp.1204989 22739103
Greenland S. 1996. Basic methods for sensitivity analysis of biases. Int J Epidemiol. 25(6):1107–1116. https://academic.oup.com/ije/article/25/6/1107/672425. 10.1093/ije/25.6.1107 9027513
Health and Safety Executive (HSE). 2019. Change in enforcement expectations for mild steel welding fume. Merseyside, UK: Health and Safety Executive. https://www.hse.gov.uk/safetybulletins/mild-steel-welding-fume.htm
Hernán MA, Hernández-Díaz S, Robins JM. 2004. A structural approach to selection bias. Epidemiology. 15(5):615–625. 10.1097/01.ede.0000135174.63482.43 15308962
Higgins JPT, Thompson SG. 2002. Quantifying heterogeneity in a meta-analysis. Stat Med. 21(11):1539–1558. 10.1002/sim.1186 12111919
Higgins JPT, Thompson SG, Deeks JJ, Altman DG. 2003. Measuring inconsistency in meta-analyses. BMJ. 327(7414):557–560. 10.1136/bmj.327.7414.557 12958120
Higgins JPT, Thompson SG, Spiegelhalter DJ. 2009. A re-evaluation of random-effects meta-analysis. J R Stat Soc Ser A Stat Soc. 172(1):137–159. 10.1111/j.1467-985X.2008.00552.x 19381330
Honaryar MK, Lunn RM, Luce D, Ahrens W, ’t Mannetje A, Hansen J, Bouaoun L, Loomis D, Byrnes G, Vilahur N, et al. 2019. Welding fumes and lung cancer: A meta-analysis of case-control and cohort studies. Occup Environ Med. 76(6):422–431. 10.1136/oemed-2018-105447 30948521
Howard BE, Phillips J, Tandon A, Maharana A, Elmore R, Mav D, Sedykh A, Thayer K, Merrick BA, Walker V, et al. 2020. SWIFT-Active Screener: Accelerated document screening through active learning and integrated recall estimation. Environ Int. 138:105623. 10.1016/j.envint.2020.105623 32203803
International Agency for Research on Cancer (IARC). 2004. Some drinking-water disinfectants and contaminants, including arsenic. IARC Monogr Eval Carcinog Risks Hum. 84 . Lyon, France: International Agency for Research on Cancer. https://publications.iarc.fr/102 ].
International Agency for Research on Cancer (IARC). 2012. Arsenic, metals, fibres, and dusts. IARC Monogr Eval Carcinog Risks Hum. 100C . Lyon, France: International Agency for Research on Cancer. https://publications.iarc.fr/120 ].
International Agency for Research on Cancer (IARC). 2018. Drinking coffee, mate, and very hot beverages. IARC Monogr Eval Carcinog Risks Hum. 116 . Lyon, France: International Agency for Research on Cancer. https://publications.iarc.fr/566 ].
International Agency for Research on Cancer (IARC). 2019. Preamble to the IARC monographs. Lyon, France: International Agency for Research on Cancer. https://monographs.iarc.who.int/iarc-monographs-preamble-preamble-to-the-iarc-monographs/
International Agency for Research on Cancer (IARC). 2021. Instructions for authors for the preparation of drafts for IARC monographs. Lyon, France: International Agency for Research on Cancer. https://monographs.iarc.who.int/wp-content/uploads/2018/06/2021-Instructions-for-Authors.pdf
International Agency for Research on Cancer (IARC). 2022. Cancer today [GLOBOCAN]. Lyon, France: International Agency for Research on Cancer. https://gco.iarc.fr/today/home
International Agency for Research on Cancer (IARC). 2024. Statistical methods in cancer research volume V: Bias assessment in case-control and cohort studies for hazard identification. Berrington de González A, Richardson DB, Schubauer-Berigan MK, editors. Lyon, France: International Agency for Research on Cancer. https://publications.iarc.who.int/634
Jager KJ, Zoccali C, MacLeod A, Dekker FW. 2008. Confounding: What it is and how to deal with it. Kidney Int. 73(3):256–260. 10.1038/sj.ki.5002650 17978811
James MK, Miller ME, Anderson RT, Worley AS, Longino CF Jr. 1997. Benefits of linkage to the National Death Index in the Longitudinal Study of Aging. J Aging Health. 9(3):298–315. 10.1177/089826439700900302 10182395
Jewkes R, Wood K. 1998. Competing discourses of vital registration and personhood: Perspectives from rural South Africa. Soc Sci Med. 46(8):1043–1056. 10.1016/S0277-9536(97)10036-3 9579756
Kleinbaum DG, Kupper LL, Morgenstern H. 1982. Epidemiologic research: Principles and quantitative methods. New York, NY: Van Nostrand Reinhold.
Kristensen P. 1992. Bias from nondifferential but dependent misclassification of exposure and outcome. Epidemiology. 3(3):210–215. 10.1097/00001648-199205000-00005 1591319
Kristman V, Manno M, Côté P. 2004. Loss to follow-up in cohort studies: How much is too much? Eur J Epidemiol. 19(8):751–760. 10.1023/B:EJEP.0000036568.02655.f8 15469032
Lash TL, Fox MP, MacLehose RF, Maldonado G, McCandless LC, Greenland S. 2014. Good practices for quantitative bias analysis. Int J Epidemiol. 43(6):1969–1985. 10.1093/ije/dyu149 25080530
Lawlor DA, Tilling K, Davey Smith G. 2016. Triangulation in aetiological epidemiology. Int J Epidemiol. 45(6):1866–1886. 28108528
Linet MS, Schubauer-Berigan MK, Berrington de González A. 2020. Outcome assessment in epidemiological studies of low-dose radiation exposure and cancer risks: Sources, level of ascertainment, and misclassification. J Natl Cancer Inst Monogr.(56):154–175. 10.1093/jncimonographs/lgaa007 32657350
MacLehose RF, Ahern TP, Lash TL, Poole C, Greenland S. 2021. The importance of making assumptions in bias analysis. Epidemiology. 32(5):617–624. 10.1097/EDE.0000000000001381 34224472
Macaskill P, Walter SD, Irwig L. 2001. A comparison of methods to detect publication bias in meta-analysis. Stat Med. 20(4):641–654. 10.1002/sim.698 11223905
Marjerrison N, Jakobsen J, Demers PA, Grimsrud TK, Hansen J, Martinsen JI, Nordby KC, Veierød MB, Kjærheim K. 2022. Comparison of cancer incidence and mortality in the Norwegian Fire Departments Cohort, 1960-2018. Occup Environ Med. 79(11):736–743. 10.1136/oemed-2022-108331 35589382
National Cancer Institute (NCI). 2022. Surveillance, Epidemiology, and End Results (SEER) Program. Bethesda, MD: National Institutes of Health, National Cancer Institute. https://seer.cancer.gov/
National Center for Health Statistics (NCHS). 2013. National Death Index: User’s guide. Hyattsville, MD: Centers for Disease Control and Prevention, National Center for Health Statistics. [Accessed: April 9, 2025]. https://stacks.cdc.gov/view/cdc/21958
National Toxicology Program (NTP). 2015. Report on Carcinogens monograph on trichloroethylene. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. RoC Monograph 05. 10.22427/ROC-MGRAPH-5
National Toxicology Program (NTP). 2021a. NTP cancer hazard assessment report on night shift work and light at night. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/NTP-CHR-NSWLAN
National Toxicology Program (NTP). 2021b. Substance profile: o-Toluidine. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2021c. Substance profile: Tobacco-related exposures: Environmental tobacco smoke. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2021d. Substance profile: Viruses, eight listings. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
National Toxicology Program (NTP). 2023. 15th RoC Dashboard. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. [Last updated: March 7, 2023]. https://ntp.niehs.nih.gov/go/RoC15data
Nohr EA, Liew Z. 2018. How to investigate and adjust for selection bias in cohort studies. Acta Obstet Gynecol Scand. 97(4):407–416. 10.1111/aogs.13319 29415329
Patel KV, Eschbach K, Ray LA, Markides KS. 2004. Evaluation of mortality data for older Mexican Americans: Implications for the Hispanic paradox. Am J Epidemiol. 159(7):707–715. 10.1093/aje/kwh089 15033649
Pearce N, Checkoway H, Kriebel D. 2007. Bias in occupational epidemiology studies. Occup Environ Med. 64(8):562–568. 10.1136/oem.2006.026690 17053019
Pearce N, Richiardi L. 2014. Commentary: Three worlds collide: Berkson’s bias, selection bias and collider bias. Int J Epidemiol. 43(2):521–524. 10.1093/ije/dyu025 24585732
Picciotto S, Brown DM, Chevrier J, Eisen EA. 2013. Healthy worker survivor bias: Implications of truncating follow-up at employment termination. Occup Environ Med. 70(10):736–742. 10.1136/oemed-2012-101332 23873985
Rothman KJ, Greenland S. 2005. Causation and causal inference in epidemiology. Am J Public Health. 95 Suppl 1:S144–S150. 10.2105/AJPH.2004.059204 16030331
Rothman KJ, Greenland S, Lash TL. 2008. Modern epidemiology. 3rd ed. Philadelphia, PA: Lippincott, Williams, and Wilkins.
Samet JM, Chiu WA, Cogliano V, Jinot J, Kriebel D, Lunn RM, Beland FA, Bero L, Browne P, Fritschi L, et al. 2020. The IARC monographs: Updated procedures for modern and transparent evidence synthesis in cancer hazard identification. J Natl Cancer Inst. 112(1):30–37. 10.1093/jnci/djz169 31498409
Savitz DA, Wellenius GA. 2023. Can cross-sectional studies contribute to causal inference? It depends. Am J Epidemiol. 192(4):514–516. 10.1093/aje/kwac037 35231933
Schwartzbaum J, Ahlbom A, Feychting M. 2007. Cohort study of cancer risk among male and female shift workers. Scand J Work Environ Health. 33(5):336–343. 10.5271/sjweh.1150 17973059
Scott CS, Jinot J. 2011. Trichloroethylene and cancer: Systematic and quantitative review of epidemiologic evidence for identifying hazards. Int J Environ Res Public Health. 8(11):4238–4272. 10.3390/ijerph8114238 22163205
Shapiro AJ, Antoni S, Guyton KZ, Lunn RM, Loomis D, Rusyn I, Jahnke GD, Schwingl PJ, Mehta SS, Addington J, et al. 2018. Software tools to facilitate systematic review used for cancer hazard identification. Environ Health Perspect. 126(10):104501. 10.1289/EHP4224 30392397
Siddiqui AH, Zafar SN. 2018. Global availability of cancer registry data. J Glob Oncol. 4:1–3. 30085880
Smith MT, Guyton KZ, Gibbons CF, Fritz JM, Portier CJ, Rusyn I, DeMarini DM, Caldwell JC, Kavlock RJ, Lambert PF, et al. 2016. Key characteristics of carcinogens as a basis for organizing data on mechanisms of carcinogenesis. Environ Health Perspect. 124(6):713–721. 10.1289/ehp.1509912 26600562
Smith TJ, Kriebel D. 2010. A biologic approach to environmental assessment and epidemiology. New York, NY: Oxford University Press. 10.1093/acprof:oso/9780195141566.001.0001
Snoep JD, Morabia A, Hernández-Díaz S, Hernán MA, Vandenbroucke JP. 2014. Commentary: A structural approach to Berkson’s fallacy and a guide to a history of opinions about it. Int J Epidemiol. 43(2):515–521. 10.1093/ije/dyu026 24585735
Soskolne CL, Kramer S, Ramos-Bonilla JP, Mandrioli D, Sass J, Gochfeld M, Cranor CF, Advani S, Bero LA. 2021. Toolkit for detecting misused epidemiological methods. Environ Health. 20(1):90. 10.1186/s12940-021-00771-6 34412643
Stayner L, Steenland K, Dosemeci M, Hertz-Picciotto I. 2003. Attenuation of exposure-response curves in occupational cohort studies at high exposure levels. Scand J Work Environ Health. 29(4):317–324. 10.5271/sjweh.737 12934726
Steenland K, Schubauer-Berigan MK, Vermeulen R, Lunn RM, Straif K, Zahm S, Stewart P, Arroyave WD, Mehta SS, Pearce N. 2020. Risk of bias assessments and evidence syntheses for observational epidemiologic studies of environmental and occupational exposures: Strengths and limitations. Environ Health Perspect. 128(9):95002. 10.1289/EHP6980 32924579
Sterne JAC, Higgins JPT, Reeves BC.on behalf of the development group for ACROBAT-NRSI. 2014. A Cochrane risk of bias assessment tool: For non-randomized studies of interventions (ACROBAT-NRSI), version 1.0.0, 24 September 2014. Bristol, UK: University of Bristol. https://www.bristol.ac.uk/population-health-sciences/centres/cresyda/barr/riskofbias/robins-i/acrobat-nrsi/
Sterne JAC, Tilling K. 2002. G-estimation of causal effects, allowing for time-varying confounding. Stata J. 2(2):164–182. 10.1177/1536867X0200200205
Torre LA, Siegel RL, Ward EM, Jemal A. 2016. Global cancer incidence and mortality rates and trends—An update. Cancer Epidemiol Biomarkers Prev. 25(1):16–27. 10.1158/1055-9965.EPI-15-0578 26667886
U.S. Environmental Protection Agency (USEPA). 2022. ORD staff handbook for developing IRIS assessments (2022). Washington, DC: U.S. Environmental Protection Agency, Office of Research and Development. EPA Report No. EPA/600/R-22/268. https://cfpub.epa.gov/ncea/iris_drafts/recordisplay.cfm?deid=356370
Vandenbroucke JP, Broadbent A, Pearce N. 2016. Causality and causal inference in epidemiology: The need for a pluralistic approach. Int J Epidemiol. 45(6):1776–1786. 10.1093/ije/dyv341 26800751
Vandenbroucke JP, von Elm E, Altman DG, Gøtzsche PC, Mulrow CD, Pocock SJ, Poole C, Schlesselman JJ, Egger M, STROBE Initiative. 2007. Strengthening the Reporting of Observational Studies in Epidemiology (STROBE): Explanation and elaboration. PLoS Med. 4(10):e297. 10.1371/journal.pmed.0040297 17941715
VanderWeele TJ, Ding P. 2017. Sensitivity analysis in observational research: Introducing the E-value. Ann Intern Med. 167(4):268–274. 10.7326/M16-2607 28693043
von Elm E, Altman DG, Egger M, Pocock SJ, Gøtzsche PC, Vandenbroucke JP. 2007. The Strengthening the Reporting of Observational Studies in Epidemiology (STROBE) statement: Guidelines for reporting observational studies. Lancet. 370(9596):1453–1457. 10.1016/S0140-6736(07)61602-X 18064739
Vrijheid M, Deltour I, Krewski D, Sanchez M, Cardis E. 2006. The effects of recall errors and of selection bias in epidemiologic studies of mobile phone use and cancer risk. J Expo Sci Environ Epidemiol. 16(4):371–384. 10.1038/sj.jes.7500509 16773122
Wasserstein RL, Schirm AL, Lazar NA. 2019. Moving to a world beyond “p < 0.05”. Am Stat. 73 Suppl 1:1–19. 10.1080/00031305.2019.1583913
Yland JJ, Wesselink AK, Lash TL, Fox MP. 2022. Misconceptions about the direction of bias from nondifferential misclassification. Am J Epidemiol. 191(8):1485–1495. 10.1093/aje/kwac035 35231925