# 2 Evaluation of Human Exposure Data

## Summary

The aim of the human exposure section is to provide information on evaluating the extent of exposure and how people are exposed to a specific substance. This task is accomplished by: (1) establishing a human exposure data evaluation framework, (2) extracting and organizing the data, and (3) evaluating, integrating, and summarizing the evidence.

Establishing the evaluation framework (Section 2.1) includes defining and characterizing the substance to represent real-world human exposure, developing a literature search strategy and mapping studies by type of information and type of publication, and developing a short protocol. The human exposure protocol identifies any substance-specific exposure issues and provides transparency regarding the literature searches and approach for reaching decisions on key questions guiding the search for human exposure data.

Extracting and organizing the data (Section 2.2) involves taking relevant exposure information from sources identified from literature searches and arranging the information in tables based on the type of information (e.g., levels in the environment or biomonitoring data) and exposure sources. General study quality considerations are evaluated to provide context for understanding how the data affect answers to key questions.

Evaluating, integrating, and summarizing the evidence (Section 2.3) involves assessing extracted data to answer key questions. Data types are integrated to support conclusions about level and extent of human exposure.

## Introduction and Objective

This section describes the methods used to identify, summarize, and interpret human exposure data for substances under evaluation for carcinogenicity for either Report on Carcinogens (RoC) monographs or other cancer hazard evaluation documents. The approach has been updated since the 2015 RoC handbook. The objective of this human exposure section is to provide information on evaluating extent of exposure and how people are exposed to a specific substance. It does not include a formal exposure assessment or evaluate health risks associated with various levels of exposure or provide a comprehensive review of all exposure information.

The specific objective of this section is to provide the information necessary to determine whether a significant number of people residing in the United States are exposed to the substance under review, as required by the congressional mandate (see Introduction). Past exposure can fulfill this criterion due to, in part, the long-latency period for many types of cancer. The congressional mandate does not provide guidance to interpret “significant” exposure, and information on numbers of exposed individuals is rarely available. However, significant exposure can be inferred from other types of information, such as use and production; occurrence in the environment, workplace, food, consumer, or medical products; and exposure levels in people.

Human exposure data typically are summarized using authoritative sources supplemented with contemporary reviews and more recent primary studies if they are needed to inform the objectives and answer key questions. The amount of available exposure information varies for different substances and scientific judgment is required to determine when the level of evidence meets the criterion. Data from all geographical locations are included as non-U.S. studies can provide information on the extent of exposure and how people are exposed to a specific substance that is relevant to U.S. residents and globally.

### Key Questions

The questions below guide the search for information summarized in the exposure section.

#### Primary Question

- Are a significant number of people living in the United States exposed to the candidate substance and, if so, what is the evidence supporting this conclusion?

#### Secondary Questions

- How should the substance be defined and characterized? Ideally, the definition should represent real-world human exposure.
- How and where are (were) people exposed to the substance (sources, settings, levels, frequency, trends)?
- What are the most important sources of exposure?
- What federal regulations and guidelines limit (or potentially limit) exposure?
- What are other ways to decrease or prevent exposure?

### Components of the Evaluation of Human Exposure Data

- Develop the framework (Section 2.1).
  - Develop a literature search strategy and search, select, and map the literature.
  - Develop approach and protocol.
- Extract and organize the data (Section 2.2).
- Evaluate, integrate, and summarize the evidence (Section 2.3).

## 2.1 Evaluation Framework Development

Scoping and problem-formulation activities are conducted to identify and determine the key issues and relevant literature.

### 2.1.1 Substance Characterization

The candidate substance should be defined and characterized to represent real-world human exposure, which is especially important when evaluating complex exposure scenarios or mixtures. For example, pentachlorophenol was redefined as a mixture based on exposure data showing that people who are exposed to pentachlorophenol are also exposed to by-products of its synthesis. Another example is night shift work, which is defined as working during the biological night (e.g., 12 a.m. to 5 a.m.) and as a complex exposure scenario including exposure to light at night, sleep disruption, altered meal timing, and stress and behavior factors.

### 2.1.2 Literature Search Strategy and Evidence Mapping

Before selecting the substance for evaluation, the initial step is to estimate the extent of U.S. exposure to the substance using authoritative and online sources, starting with EPA’s CompTox toxicological profiles, which include sources such as IRIS (Integrated Risk Information System) and ATSDR (Agency for Toxic Substances and Disease Registry), and supplementing with other sources (e.g., USGS Commodity Reports and NIOSH Health Hazard Evaluations) or journal review articles. A full list of the general sources can be found in Appendix B. Reviews and other exposure studies are typically retrieved from citation database searches for cancer and mechanistic data that are conducted in the scoping and problem-formulation activities. Targeted literature searches for exposure information may be conducted to address gaps.

Once the substance has been selected for review, the extent of the literature search is determined on a case-by-case basis, largely depending on the availability of data from the authoritative sources and information retrieved during the scoping and problem-formulation searches. Focused citation database searches using selected standard exposure search terms (see Table 2-1) and possible searches of grey literature may be used. This process is iterative and answers key questions, updates literature from authoritative sources or reviews, and usually focuses on the most informative type of exposure information, such as biomonitoring studies.

The literature search strategy, substance-specific search terms, and associated inclusion/exclusion criteria used to identify the relevant literature are constructed in consultation with an information specialist. Table 2-1 lists examples of general exposure-related search terms, including text words and Medical Subject Heading [MeSH] terms used in PubMed. These terms are used in conjunction (using the Boolean operator “AND”) with the substance-specific terms or metabolites of the substances. Additional exposure or substance-related search terms may be added to fully capture all exposure scenarios.

Search terms for the substance may include chemical synonyms or exposure scenarios associated with exposure to the specific substance. The former is usually identified from EPA’s CompTox Dashboard or National Library of Medicine databases (e.g., ChemIDplus, HSDB), and exposure scenarios are identified from secondary sources. Standard RoC exposure-related search strings can be found in the search string document on the RoC website (https://ntp.niehs.nih.gov/ntp/roc/handbook/rochandbookappendix_508.pdf).

Table 2-1 Examples of Concepts for Searches for Exposure Information

PubMed, Scopus, and Web of Science | MeSH Terms Used in PubMed
Occurrence Environmental pollution Environmental exposure/monitoring Occupational exposure/monitoring Biomonitoring Indoor air or air pollution Prevention/intervention | Environmental pollutants Environmental pollution Occupational exposure Biomarkers Prevention and control [subheading] Climate change

The literature search is followed by selection and mapping of studies by the type of information (e.g., uses or sources of exposure) and type of publication (e.g., review or primary research publication). Citations retrieved from literature searches are uploaded to a web-based systematic review software such as the Health Assessment Workspace Collaborative (HAWC) and screened by a reviewer using predefined inclusion/exclusion criteria based on the research question. Exposure information should be specific for the substance. Data from authoritative sources or published articles are initially included in the review if they meet the inclusion criteria for providing relevant information (see Table 2-2 for more details):

- Information on production, export, import, and uses
- Occurrence data (such as levels in the environment or workplace, food, consumer, or medical products; toxics release data)
- Exposure data, such as intake and personal and biomonitoring data (e.g., urine, blood, or tissue data)

### 2.1.3 Framework and Protocol Development

Typically, a short protocol for evaluating human exposure data is included with the protocol for other parts of the evaluation (such as human cancer or mechanistic data). The protocol identifies any substance-specific exposure issues and provides transparency for the literature searches (see Section 1.2.2) and approach for reaching decisions on the key questions. This information may include data on uses; production; occurrence; and environmental, occupational, and consumer product exposures (see Table 2-2). In cases for which highly informative data (e.g., estimates of numbers of exposed people, modeled exposure levels from specific sources, biomonitoring data) are not available from the standard sources but are available from published articles (i.e., primary data), these data can be used to address primary and secondary questions. For example, a study reporting biological measurement data (such as urinary metabolite levels) or air concentrations for a group of workers employed by a company in an emerging industry or a company using a new manufacturing process could provide key occupational exposure information for the review.

## 2.2 Organization and Extraction of Exposure Data

Once studies are identified that meet the inclusion criteria for providing relevant exposure information, the data are extracted into tables and organized by the type of information and exposure sources. General quality considerations are evaluated; however, there is no formal risk-of-bias assessment.

### 2.2.1 Types of Information

In general, the types of data included in exposure sections of either RoC monographs or other cancer hazard evaluation documents include: (1) use and production-related information, (2) occurrence (e.g., levels in the environment), (3) measured or modeled human exposure (e.g., biomonitoring data such as urine levels), and (4) prevention related information (e.g., regulations and interventions) Information presented in the human exposure section can vary considerably depending on the substance. Table 2-2 lists general categories of exposure information, types of data in each category, and examples of literature sources for each type of data, which is organized by the type of data and source of exposure. Each source of exposure may include different types of data, e.g., environmental exposure may include releases and occurrence, as well as modeled exposure.

Table 2-2 Exposure-related Data

Data Category | Types of Data | Literature Sources
Production | Present and past production, import, export, or consumption Trends in use or production over time | United States International Trade Commission DataWeb (USITC 2023) USEPA Chemical Data Reporting rule (USEPA 2023b)
Uses | Present and past uses Identification of most widespread or important uses | USEPA CompTox Chemicals Dashboard (USEPA 2023c) Ullmann’s Encyclopedia of Industrial Chemistry (Ley 2002) Trade association publications Authoritative sources, reviews, and primary literature
Occurrence and Exposure Data
Occupational Exposure | Number of exposed workers, types of industries, exposure levels (personal, ambient, and biomonitoring data), and exposure trends; modeling data if available | NIOSH Health Hazard Evaluations (NIOSH 2019) OSHA Chemical Exposure Health Data (OSHA 2023) Authoritative sources, reviews, and primary literature
Environmental exposure/occurrence (group not individual) | Release data, occurrence levels in ambient and indoor air, water, soil, and dust, modeling data, if available, of numbers of exposed people | USEPA Toxics Release Inventory (USEPA 2023e) Authoritative sources, reviews, and primary literature
Consumer products including smoking | Percentage of products containing chemical, percentage of total volatile organic compounds (VOCs) emitted from product groups, emissions from various products (e.g., emissions from wood and wood-based materials used in furniture and building products), or occurrence (levels) | Chemical and Products Database (CPDat)^a^ (USEPA 2023a) Consumer Product Information Database (CPID) (DeLima Associates 2023) Authoritative sources, reviews, and primary literature
Medical use | Prevalance and dose | Medical databases such as the Medical Expenditure Panel Survey (AHRQ 2024) and FDA Drug Databases, such as Drugs at FDA (FDA 2024a)
Food and drinking water | Occurrence (levels) and intake, exposure (modeled intake) | FDA Total Diet Study (FDA 2024b) USEPA Safe Drinking Water Act (USEPA 2023d) national compliance data Authoritative sources, reviews, reviews, and primary literature
Prevalence and transmission of biological agents | Exposure in different populations | CDC, NIAID (NIAID 2023) Authoritative sources, reviews, and primary literature
Personal and biological monitoring | Personal monitoring data Information related to interpreting biological indices used in exposure studies Data on levels and trends of the substance (or metabolite when relevant) in human tissues or samples measured in studies Modeled intake levels from various environmental, occupational, or other sources | National Health and Nutrition Examination Survey (NHANES) (CDC 2023) Agency for Toxic Substances and Disease Registry Toxicological Profiles (ATSDR 2023) Authoritative sources, reviews, and primary literature
Prevention and Intervention
Prevention and intervention | Occupational: engineering controls, modified work practices, PPE Environmental: engineering controls and PPE Personal behaviors including consumer products, diet, etc.; behavior risk factor modification Biologicals: behavioral risk factor modification, blood supply screening, and vaccines and drug treatments | Substance-specific authoritative sources, reviews, and primary literature
Guidance and regulations | The congressional madidate requires providing information regarding federal regulations and guidelines to limit exposure | Websites for U.S. government agencies (e.g., USEPA, NIOSH) Websites for authoritative nongovernmental sources (e.g., ACGIH) (ACGIH 2023) The CFR (GPO 2023), using a keyword search across all 50 titles of the CFR simultaneously to identify regulations beyond those listed on government websites

ACGIH = American Conference of Governmental Industrial Hygienist; CDC = Centers for Disease Control and Prevention; CFR = Code of Federal Regulations; FDA = Food and Drug Administration; NHANES = National Health and Nutrition Examination Survey; NIAID = National Institute of Allergy and Infectious Disease; NIOSH = National Institute of Occupational Safety and Health; OSHA = The Occupational Safety and Health Administration; PPE = personal protective equipment; USEPA = U.S. Environmental Protection Agency; VOCs = volatile organic compounds.

^a^ The Chemical and Products database (CPDat) is part of EPA’s Computational Toxicology (CompTox) Dashboard.

### 2.2.2 Data Extraction Methods

Data are extracted in a systematic manner using web-based tools such as Table Builder (Shapiro et al. 2018) to create Word tables, manually created Word tables, or text. Examples of the type of exposure information extracted include sample matrix and method, number of measurements, measurement duration, exposure level and range, chemical composition data for consumer products, and description of exposed group.

Quality assurance of data extraction and data entry into tables (such as those created by Table Builder) are accomplished by review of data entry by an independent reviewer, and discrepancies are resolved via follow-up discussion of the source data.

### 2.2.3 Study Informativeness Considerations

Exposure data are evaluated to identify any general limitations such as reliability of the analytical methods, the choice of biological media as they relate to the likely route of exposure, and the final or preliminary nature of a data set (e.g., a draft version of an emissions report). For example, these evaluations could be accomplished by review of analytical method development and demonstration documentation or case-by-case consideration of whether to include draft report data depending on how informative the data set is for answering primary and secondary questions. No formal risk-of-bias review is conducted for exposure studies; however, consideration of general strengths and limitations of exposure data and studies provides context for understanding how the data affect conclusions about key questions.

## 2.3 Evidence Summarization

The extracted data are reviewed and evaluated to answer the key questions (e.g., whether a significant number of people in the United States are exposed to the substance and the nature of exposure). All evidence streams are integrated to support the conclusions.

### 2.3.1 Informativeness of Data Types

The estimated number of exposed people directly addresses the congressional madidate. Other types of data provide information on the level of exposure, such as biomonitoring data—substances or metabolites measured in blood, tissue, or urine—especially for samples for large numbers of people (e.g., NHANES) or of workers, personal monitoring data, or modeled biological exposure estimates (e.g., intake from food). The next tiers of informative data relate to occurrence: measured levels in the environment (e.g., ambient air), in the workplace, or in consumer products, food, and medicines, etc., followed by estimates of releases to the environment (e.g., industrial releases to air from TRI) and data on prevalence of chemicals in consumer product compositions or market use. Ideally, data should be available for higher exposure scenarios (e.g., environmental measurements taken near a manufacturing plant versus general ambient air) or more directly related to how people are exposed (e.g., drinking water versus surface water). Production, import, and export levels are the least informative data. Integration across these types of data may compensate for limitations for specific types of data and all data are useful for determining how and where people are exposed. Table 2-3 lists examples of exposure data types in their general order of prioritization. Appendix B contains examples of sources of exposure information for the U.S. and other countries.

Significant U.S. exposure is not always defined only by the extent of exposure (numbers of exposed people) and can include consideration of the level of exposure. In some cases, available occupational exposure data might indicate that exposure levels are high but germane to few people in that setting. Similar considerations include sensitive subpopulations (e.g., infants, elderly, immunologically compromised) and environmental justice concerns, resulting in potential disparities to disproportionally affected populations (e.g., race and ethnicity, gender, socioeconomic status) that may be more sensitive to exposure, have higher exposure levels, or both.

Because the overall objective is to determine whether the exposure information meets the requirement for listing a substance in the RoC (i.e., significant number of U.S. residents are exposed to the substance) generally, U.S. data are most informative; however, these data can be supplemented with data from other countries to provide context for answering specific key questions. For example, data from countries in Europe, Asia, or other region on exposure associated with manufacturing processes, industrial uses, or the general population’s use of products containing the substance can also be useful if the processes and products are comparable with those in the United States.

Table 2-3 Examples of Exposure Data Types

Data Type/Category | Level or Extent of Exposure | Example
Estimated Number of Exposed People | Extent | Workers: Company-reported or government agency estimates of number of exposed workers General population: Census or other government records (USCB 2023), number of people living near sources of pollution, utility users (e.g., public water)
Exposure Models | Level | Estimated exposure from specific sources [e.g., intake from food from the FDA total diet study (FDA 2024b)] or from multiple sources [e.g., EPA’s human exposure modeling databases (USEPA 2024)] Reporting of typical and worst-case occupational exposure estimates via use of analogous or surrogate data (e.g., extrapolation from data on exposure from production to estimate exposure in other exposure scenarios)
Biomonitoring | Level | Blood, tissue, or urine samples in a discrete group with a known source of exposure (e.g., workers or residents exposed to pollution from a chemical plant or spill) or the general population with unknown sources of exposure (e.g., NHANES)
Personal Monitoring | Level | Air concentrations measured by workers wearing badge or other samplers, or study participants in the general public wearing exposure monitoring bracelets
Occurrence | Level | Levels in the environment (outdoor, indoor air, water, soil), workplace, medicine or consumer products, food; the source of exposure may be known (e.g., workers, environmental spill, downstream from factories) or unknown (e.g., ambient air in cities)
Releases to the Environment | Extent and levels | EPA’s TRI data (USEPA 2023e) (industrial manufacturing and processing emissions)
Prevalence in Industrial, Medical, Consumer Products, Food | Extent | Chemical use data reported in EPA’s CompTox Chemicals Dashboard (USEPA 2023c) Chemical composition data reported in the Consumer Product Information Database (DeLima Associates 2023) Trade association consumption pattern reports
Production or Import/Export Information for the Substance | Level | Import/export data reported in United States International Trade Commission DataWeb database (USITC 2023)

### 2.3.2 Conclusions

Exposure data are synthesized by concisely summarizing data from the different data types to answer the key questions and draw conclusions about whether a significant number of people in the United States are (or were) exposed; how and where people are exposed; what the major sources of exposure are; trends in sources, settings, levels, and frequency of exposure over time; and ways to decrease or prevent exposure.

The importance of the available exposure data can vary by substance and is outlined in the protocol. For example, the conclusions could be presented by the most important source of exposure on the basis of exposure levels (e.g., occupational exposure; general population exposure from air, water, and food; and environmental exposure); the most important exposure route (e.g., inhalation, ingestion, dermal); or most recently available updated data (e.g., updated general population emissions data).

## References

Agency for Healthcare Research and Quality (AHRQ). 2024. Medical Expenditure Panel Survey (MEPS). Rockville, MD: Agency for Healthcare Research and Quality. https://meps.ahrq.gov/mepsweb/
Agency for Toxic Substances and Disease Registry (ATSDR). 2023. [Homepage]. Atlanta, GA: Centers for Disease Control and Prevention, Agency for Toxic Substances and Disease Registry. https://www.atsdr.cdc.gov/
American Conference of Governmental Industrial Hygienists (ACGIH). 2023. [Homepage]. Cincinnati, OH: ACGIH. https://www.acgih.org/
Centers for Disease Control and Prevention (CDC). 2023. NHANES: National Health and Nutrition Examination Survey. Hyattsville, MD: Centers for Disease Control and Prevention, National Center for Health Statistics. [Accessed: May 31, 2023]. https://www.cdc.gov/nchs/nhanes/index.htm
DeLima Associates. 2023. CPID: Consumer Product Information Database. McLean, VA: DeLima Associates. https://www.whatsinproducts.com/
Ley C. 2002. Ullmann's encyclopedia of industrial chemistry. 6th ed. Weinheim, Germany: Wiley-VCH. 10.1002/14356007
National Institute for Occupational Safety and Health (NIOSH). 2019. Health Hazard Evaluations (HHEs). Cincinnati, OH: Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health. [Last reviewed: November 30, 2019]. https://www.cdc.gov/niosh/hhe/default.html
National Institute of Allergy and Infectious Diseases (NIAID). 2023. [Homepage]. Bethesda, MD: National Institutes of Health, National Institute of Allergy and Infectious Diseases. https://www.niaid.nih.gov/
Occupational Safety and Health Administration (OSHA). 2023. Chemical Exposure Health Data. Washington, DC: U.S. Department of Labor, Occupational Safety and Health Administration. https://www.osha.gov/opengov/health-samples
Shapiro AJ, Antoni S, Guyton KZ, Lunn RM, Loomis D, Rusyn I, Jahnke GD, Schwingl PJ, Mehta SS, Addington J, et al. 2018. Software tools to facilitate systematic review used for cancer hazard identification. Environ Health Perspect. 126(10):104501. 10.1289/EHP4224 30392397
U.S. Census Bureau (USCB). 2023. [Homepage]. Suitland, MD: U.S. Department of Commerce, U.S. Census Bureau. https://www.census.gov/
U.S. Environmental Protection Agency (USEPA). 2023a. Chemical and Products Database (CPDat). Washington, DC: U.S. Environmental Protection Agency. [Last updated: March 6, 2023]. https://www.epa.gov/chemical-research/chemical-and-products-database-cpdat
U.S. Environmental Protection Agency (USEPA). 2023b. Chemical Data Reporting under the Toxic Substances Control Act. Washington, DC: U.S. Environmental Protection Agency. [Accessed: January 26, 2023]. https://www.epa.gov/chemical-data-reporting
U.S. Environmental Protection Agency (USEPA). 2023c. CompTox Chemicals Dashboard. Washington, DC: U.S. Environmental Protection Agency. [Last updated: November 29, 2023]. https://www.epa.gov/chemical-research/comptox-chemicals-dashboard
U.S. Environmental Protection Agency (USEPA). 2023d. Safe Drinking Water Act (SDWA). Washington, DC: U.S. Environmental Protection Agency. [Last updated: March 30, 2023]. https://www.epa.gov/sdwa
U.S. Environmental Protection Agency (USEPA). 2023e. Toxic Release Inventory (TRI) Program. Washington, DC: U.S. Environmental Protection Agency. [Last updated: July 24, 2023]. https://www.epa.gov/toxics-release-inventory-tri-program
U.S. Environmental Protection Agency (USEPA). 2024. Air: Fate, Exposure, and Risk Analysis (FERA): Human exposure modeling - Databases to support exposure modeling. Washington, DC: U.S. Environmental Protection Agency. [Accessed: May 9, 2024]. https://www.epa.gov/fera/human-exposure-modeling-databases-support-exposure-modeling
U.S. Food and Drug Administration (FDA). 2024a. About Drugs@FDA. Silver Spring, MD: U.S. Food and Drug Administration. https://www.fda.gov/drugs/drug-approvals-and-databases/about-drugsfda
U.S. Food and Drug Administration (FDA). 2024b. FDA Total Diet Study (TDS). Silver Spring, MD: U.S. Food and Drug Administration. https://www.fda.gov/food/science-research-food/fda-total-diet-study-tds
U.S. Government Publishing Office (GPO). 2023. Code of Federal Regulations (annual edition). Washington, DC: U.S. Government Publishing Office. https://www.govinfo.gov/app/collection/cfr
United States International Trade Commission (USITC). 2023. DataWeb. Washington, DC: United States International Trade Commission. [Accessed: May 27, 2023]. https://dataweb.usitc.gov/