# 1 Initial Planning Phase

This section primarily describes scoping and problem formulation related to identifying a substance for review and general scoping methods that are relevant across all evidence streams (e.g., human cancer, animal cancer, and mechanistic studies). Scoping methods specific for an evidence stream are described in the relevant handbook sections (especially for evidence evaluated by systematic review methods, see Introduction). The planning process is iterative and includes scoping activities to identify the nominations and develop its review. A glossary of general systematic review terms as well as terms for all sections of the handbook is available in Appendix A.

Figure 1-1

Initial Planning and Scoping of a Cancer Hazard Assessment

This process is iterative, starting with scoping and problem formulation to identify the substances for review (Section 1.1) and development the framework (Section 1.2). The framework is captured in the substance-specific protocol for the evaluation and is informed by the scoping activities, including identification, selection, and mapping of the literature. The protocol is made publicly available after peer review.

## 1.1 Identify and Select Substances for Review

Substances are selected for review according to the Report on Carcinogens (RoC) process for preparing the RoC using a variety of sources (e.g., public or government nominations, authoritative evaluations, and searches of peer-reviewed literature, government, and public health-related websites) to identify substances for review for the RoC (NTP 2023b).

We determine the scope of the literature review to determine whether there is a potential public health concern to warrant a cancer hazard evaluation, e.g., evidence of U.S. exposure and an adequate database (e.g., number of studies) for evaluation. The multistep process begins with searching authoritative sources (starting with EPA CompTox) and websites (such as Agency for Toxic Substances and Disease Registry, National Institute of Occupational Safety and Health, and EPA Integrated Risk Information System, see Appendix B) for exposure and carcinogenicity information and then developing more specific literature searches of citation databases. These initial searches inform the development of the research question (exposure and cancer outcome) and the framework (e.g., included literature) for answering the question. Systematic review methodology defines the framework for studies included in the review using the terminology “PECO” (population, exposure, comparison group, and outcome). Because our cancer hazard evaluations include multiple types of evidence streams, (animal models, human populations, and cells), we have modified the PECO to EECO and replaced “population” with “evidence stream” for the overall monograph; we retained the term PECO for the human epidemiology studies and use MECO for animal studies in which M stands for model.

## 1.2 Develop the Framework

This section describes the first step in framework development, (e.g., identifying and mapping the literature). Next, the evaluation team reviews the literature and characterizes scientific and substance-specific issues for conducting the assessment, including methods for evaluating study informativeness and integrating the evidence within and across evidence streams (see the relevant sections). The monograph protocol captures the frameworks for each evidence stream.

### 1.2.1 Identify the Literature

The initial EECO informs the literature search strategy and associated inclusion/exclusion criteria. General approaches for identifying the literature are listed in Box 1-1 (see Sections 2 to 6 for guidelines for specific types of evidence).

In consultation with an information specialist, we develop a literature search strategy based on the EECO and typically search three citation databases (PubMed, Web of Science, Scopus); however, the databases and dates searched may vary on a case-by-case basis, depending on the nature of the substance and the topic.

Box 1-1 Types of Informational Searches

Database searches: The major source of identifying relevant peer-review publication papers on the relevant topics (see text for more details).

General sources: Examples include authoritative reviews, government reports, and web-based databases (see Appendix B).

Focused searches for specific scientific issues: Typically, issues that are identified at the beginning and during the literature-based review.

Secondary citations: Citations identified from the literature cited in authoritative review or primary references located by the literature search.

Updated searches: Literature searches are updated by either saving the search strategy and rerunning them or by creating monthly alerts in the appropriate databases (e.g., PubMed, Scopus, Web of Science).

Literature searches of the databases generally combine search terms for the substance with search terms for the outcome (e.g., cancer or biological effects) and, for human and animal cancer studies, search terms for the relevant evidence stream (e.g., epidemiology terms) (a list of search strings is available on the RoC web page (https://ntp.niehs.nih.gov/ntp/roc/handbook/rochandbookappendix_508.pdf)). For chemical substances, search terms usually include the substance, its synonyms, trade name(s) when relevant, the metabolites of the substance, and the chemical class to which the substance belongs. Terms for exposure scenarios or settings are often used to identify human epidemiology studies.

Before screening the literature, we evaluate the adequacy of the literature search using “seed” studies (e.g., known relevant studies, often identified from reviews).

### 1.2.2 Select and Map the Literature

Citations retrieved from literature searches (and other sources) are uploaded to web-based systematic review software for multilevel screening using inclusion/exclusion criteria based on the initial EECO. Level 1 screening is based on title and abstract and Level 2 is based on full text. Level 1 screening is typically done by one reviewer, and a second reviewer may screen a certain percentage (e.g., 10%) of the excluded literature. Included studies are manually tagged (but could be replaced by machine learning as those technologies evolved) or mapped according to evidence stream and other characteristics, such as cancer type, study design, biological effect, and publication type. These tags will vary by project, and in general, more detailed mapping occurs at Level 2 screening when the full PDF is available. Pilot screening tests are conducted to ensure that understanding of the inclusion/exclusion criteria by the reviewers. Level 2 screening and mapping is checked by a second reviewer and differences are discussed, and if needed a third reviewer is consulted.

The software and screening procedures depend on the size and scope of the retrieved literature. Screening and mapping may be conducted manually by staff or aided by machine learning.

Table 1-1 provides examples of commonly used tools for literature screening (see Appendix C for a list and description of systematic review tools). We will assess the utility of our tools and availability of new tools on a regular basis.

To assure the accuracy of the literature, we perform quarterly retraction checks for all citations for a given substance using Retraction Watch (https://retractionwatch.com/retraction-watch-database-user-guide). Additionally, we perform a retraction check prior to conducting study informativeness evaluations for human cancer, animal cancer, and mechanistic studies.

Table 1-1 Examples of Tools Used to Screen Literature

Tool^a^ | URL | Description
Health Assessment Workspace Collaborative (HAWC) | https://hawcproject.org/ | Content management system allows users to document the assessments including screening literature
Sciome Workbench for Interactive Computer-Facilitated Text-mining (SWIFT) Review | https://www.sciome.com/swift-review/ | Uses machine learning to prioritize and sort literature
SWIFT Active screener | https://www.sciome.com/ufaq-category/introduction | Uses active learning to prioritize literature

^a^ Tools used to screen literature may change or expand over time.

In some cases, limited data extraction of selected characteristics or findings may be conducted on subsets of studies to create more detailed evidence maps. These interactive maps can be visualized and explored using Tableau or similar software.

The evidence maps and visualizations of the literature can be useful to determine which elements of the literature have an adequate database (the final EECO) for the cancer hazard evaluations (e.g., human cancer types, exposure scenarios, specific mechanistic data). More detail is available in the specific evidence stream sections. In many cases, these visualizations will be made publicly available as part of the protocol or monograph for a substance.

### 1.2.3 Develop the Protocol

The monograph evaluation team develops a protocol that adapts the handbook methods to issues specific to the substance. It consists of multiple parts, one for each relevant evidence stream; the protocols for human, animal, and mechanistic studies incorporate systematic review methods and are made publicly available on the RoC website following peer review. Protocol sections that are part of the systematic review may be written and reviewed separately. A protocol includes the following sections: (1) activities related to framework development including a summary of the scoping activities, e.g., literature search strategy, evidence maps, the initial and final EECOs, and scientific issues, (2) methods for evaluating study informativeness, and (3) methods for evidence integration. Scientific issues are substance-specific issues that are important for the assessment, including study informativeness and evidence integration, and can be identified by a variety of sources, such as reviews, primary articles, and experts. For example, a scientific issue for the night shift work evaluation was the timing that women started work. For all monograph sections, data extraction is checked for accuracy by a second reviewer. Study informativeness (bias assessment and sensitivity) for relevant evidence streams is independently completed by two reviewers using substance-specific guidance adapted from the handbook for each evidence stream. (See specific sections of the handbook for developing protocols for each evidence stream).

## References

Lunn RM, Mehta SS, Jahnke GD, Wang A, Wolfe MS, Berridge BR. 2022. Cancer hazard evaluations for contemporary needs: Highlights from new National Toxicology Program evaluations and methodological advancements. J Natl Cancer Inst. 114(11):1441–1448. 10.1093/jnci/djac164 36029241
National Toxicology Program (NTP). 2015. Handbook for preparing Report on Carcinogens monographs. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, Division of the National Toxicology Program, Office of the Report on Carcinogens. https://ntp.niehs.nih.gov/go/rochandbook
National Toxicology Program (NTP). 2023a. History of the Report on Carcinogens. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. [Last updated: March 7, 2023]. https://ntp.niehs.nih.gov/whatwestudy/assessments/cancer/history/index.html
National Toxicology Program (NTP). 2023b. Report on Carcinogens process & listing criteria. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. [Last updated: March 7, 2023]. https://ntp.niehs.nih.gov/go/rocprocess