# Introduction

## Overview

The NTP Report on Carcinogens Handbook on Methods for Conducting Cancer Hazard Evaluations (herein “RoC Handbook 2025”) is an update to the handbook published in 2015 (NTP 2015). This updated handbook details systematic review and evidence-integration methods for conducting the cancer hazard evaluation of an agent, substance, mixture, or exposure circumstance (collectively referred to as “substance”) under consideration for listing in the Report on Carcinogens (RoC). Completed evaluations are published as RoC monographs.

The cancer hazard evaluation of most substances will follow the methods described in this handbook. However, in a few instances, the NTP may instead implement a streamlined approach that directly applies the RoC listing criteria to information from peer reviewed cancer hazard assessments conducted by authoritative groups such as the International Agency for Research on Cancer or to the outcomes of peer reviewed NTP toxicology and carcinogenesis studies.

Table 1 lists the sections in the handbook and the extent of revision (systematic or narrative) to each section relative to the RoC Handbook 2015. Changes to the systematic review and evidence integration methods in the RoC Handbook 2025 range from minor revisions (e.g., Section 4. Evaluation of Cancer Studies in Experimental Animals) to more substantial revisions (e.g., Section 6. Evaluation of Mechanistic Information). Noteworthy additions are: (1) systematic review methods for assessing scientific evidence from mechanistic studies and (2) approaches for providing greater clarity on evidence integration across data streams (human cancer epidemiology data, experimental animal cancer data, and cancer mechanistic data) to reach cancer hazard conclusions. The development of new systematic review approaches for assessing carcinogenicity mechanistic studies (Section 6. Evaluation of Mechanistic Information) responds to the need for well-developed methods given the increasing role of mechanistic data in cancer hazard identification (Lunn et al. 2022). Other updates to the handbook include methods to create systematic evidence maps for exploring a collection of studies, improved tools for assessing the informativeness of human cancer and experimental animal studies, greater emphasis on evaluating the impact of bias on findings from individual studies and across studies, and enhanced reporting methods to increase transparency of the assessments.

Table 1 Overview of the Handbook Sections

Section | Description^a^
Introduction | Overview of the revised handbook
1. Initial Planning Phase | Scoping and problem formulation activities are included in each section Text from RoC Handbook 2015 rewritten Additional information included in Appendix B and Appendix C
2. Evaluation of Human Exposure Data | Not a systematic review or a quantitative exposure assessment; high-level guidance Text from RoC Handbook 2015 rewritten Additional information included in Appendix B
3. Evaluation of Human Cancer Epidemiological Studies | Systematic review methods applied in this section Moderate to major revisions to text in RoC Handbook 2015
4. Evaluation of Cancer Studies in Experimental Animals | Systematic review Minor to moderate revisions to text in RoC Handbook 2015
5. Evaluation of Disposition and Toxicokinetic Data | Not a systematic review; structured guidance on approach Text from RoC Handbook 2015 rewritten Information about ADME also included in Sections 6 and 7
6. Evaluation of Mechanistic Information | Systematic review methods applied in this section Text from RoC Handbook 2015 rewritten Additional information included in Appendix D
7. Evidence Integration | Text from RoC Handbook 2015 rewritten
Appendix A: Glossary | General systematic review terms and definitions of terms used in all sections
Appendix B: General and Exposure-specific Authoritative Sources | Provides information applicable to all sections
Appendix C: Systematic Review-related Tools Used by the Report on Carcinogens Monographs | Provides information applicable to all sections
Appendix D: Background Information on Key Characteristics of Carcinogens Biomarkers and Indicators | Provides information applicable to Section 6

^a^ Description provides information about revisions to the sections relative to RoC Handbook 2015, the relationship of a specific section to other sections, and the type of review.

Lessons learned from applying the systematic review and evidence integration tools and approaches in this handbook and scientific advancements (such as New Approach Methodologies, machine learning, see Section 6.7, New Directions) will inform future updates on methods for conducting cancer hazard evaluations.

## Identifying Carcinogens: Report on Carcinogens

The Report on Carcinogens (https://ntp.niehs.nih.gov/go/roc15) is a congressionally mandated (see below) science-based document that identifies potential cancer hazards for people living in the United States (Lunn et al. 2022). Substances are listed in two categories: known to be a human carcinogen and reasonably anticipated to be a human carcinogen. The National Toxicology Program (NTP) prepares the report for the secretary of the Department of Health and Human Services (HHS) using a four-part process and established criteria (NTP 2023b). For each listed substance, the RoC includes a substance profile with information from cancer studies that is key to the listing, as well as information about use and production, potential sources of exposure, and current federal regulations to limit exposure. Each edition of the RoC is cumulative and consists of substances newly reviewed in addition to those listed in previous editions. The RoC can be used by policymakers and the public to make informed decisions about human health. A substance not meeting the RoC listing criteria is not listed in the RoC and its review is captured in an RoC appendix.

Box 1 Congressional Mandate

Section 301(b)(4) of the Public Health Service Act, as amended, requires that the Secretary, HHS, publish an annual report that contains a list of all substances (NTP 2023a)

- Which either are known to be human carcinogens or may reasonably be anticipated to be human carcinogens, and
- To which a significant number of persons residing in the United States are exposed.

## Evaluating Cancer Hazards: Report on Carcinogens Monographs

A systematic evaluation of relevant cancer studies is conducted by the RoC evaluation team to determine whether a substance should be listed in the NTP’s Report on Carcinogens (https://ntp.niehs.nih.gov/whatwestudy/assessments/cancer/index.html). The RoC monograph captures the cancer hazard evaluation, which discusses, evaluates, and integrates evidence on:

- Human exposure
- Disposition and toxicokinetics
- Human epidemiological cancer studies
- Experimental animal carcinogenicity studies
- Mechanisms of carcinogenicity

The cancer hazard evaluation process (see Figure 1) starts with a planning phase, which includes scoping and problem formulation activities to identify the substance for review and develop the framework and methods to evaluate the evidence (see Section 1). Next, the studies are assessed for informativeness (bias assessment and study sensitivity, which is the study’s ability to inform the cancer hazard evaluation), and the evidence is integrated across studies to reach a level-of-evidence conclusion (see Sections 2 to 6 for evidence-specific methods). The last step integrates the evidence across evidence streams (Section 7) to determine whether it fulfills the RoC listing criteria. Monographs are peer reviewed by substance-specific and discipline (e.g., different evidence streams) experts.

Figure 1

Cancer Hazard Evaluation Process

The schematic shows the major steps in the cancer hazard evaluation review process.