# Appendix D Background Information on Key Characteristics of Carcinogens Biomarkers and Indicators

Appendix D provides background information on the most commonly used biomarkers and indicators for each key characteristic of carcinogens (KCC). We used the term indicators for effects that are not biomarkers per se, such as outcomes (e.g., increased infection for immunosuppression), histopathology, or organ weights. Information for each KCC is captured in a table. This information can inform both the assessment of the informativeness of the mechanistic studies (see Section 6.3) and reaching conclusions of the confidence of the evidence for each KCC (see Table 6-14, Section 6.4, which provides the ideal type of evidence to reach high confidence for a given KCC).

The 2020 publication by Smith et al. was a starting point for the tables and was supplemented by additional publications. We are aware of international activities related to evaluating KCCs (e.g., the International Agency for Cancer workshop in July 2023, Key Characteristics of Cancer Assay Mapping Workgroup). The Handbook for the Report on Carcinogens (RoC) is a living document, which will be updated based on new publications and additional information on current assays (e.g., those in the KCC tables or additional ones), advancements in research related to the KCC and multi-omic data, and lessons learned from cancer hazard evaluations following this framework.

## D.1 Is Electrophilic or Can Be Metabolically Activated to Electrophiles (KCC1)

Electrophiles are electron-poor atoms or molecules that form covalent bonds with electron-rich nucleophiles. Reversible electrophilic interactions with nucleophiles mediate many important biological functions; however, irreversible adduction of cellular macromolecules (e.g., DNA) with an electrophilic xenobiotic molecule is often an initiating step for many toxicological modes of action and pathogenic processes, including cancer. Table D-1 is organized based on relevance of the subtypes for reversible interactions; within each subtype, biomarkers are arranged by specificity (e.g., specific adducts followed by total measures), and then alphabetically.

Table D-1 Background Information on Common Biomarkers or Indicators of Electrophilicity (KCC1)

Subtype | Biomarkers/Indicators | Evidence Type: Biospecimen | Persistence | Comments or Guidance
DNA adducts | Base adducts • Adenine adducts: N7, N^6^, N3, N1, C8 • Cytosine adducts: N3, N^4^, and O^2^ • Guanine adducts (most targeted): N7, N3, N^2^, N1, O^6^, C8 • Thymine adducts: N3, O^2^, and O^4^ | Exposed humans or animals: Lymphocytes, urine (humans), tissue Ex vivo, in vitro, cell-free | Day(s)-month(s) | Endpoint considerations: • Most nucleophilic sites: N3 and N7 positions of guanine and adenine • Types of adduct formation depend on reactive chemicals, the nature of electrophiles, the ability to intercalate the DNA, and steric factors. • Animal studies on certain carcinogens (e.g., PAHs) suggest that DNA adducts detected in target tissue correlate with those found in surrogate tissue/cells (e.g., leukocytes). Endpoint association with cancer: • High levels of chemical-specific or bulky DNA adducts have been associated with increased risk of several types of cancer (e.g., colon, liver, lung in smokers, prostate, and stomach) in prospective studies, albeit risk estimate could be measuring risk due to exposure rather than early biological effects because adducts are also exposure biomarker. • Animal studies have found that DNA adducts ranging from 53 to 5543 adducts/10^8^ nucleotides in rat or mouse liver are associated with a 50% tumor incidence. Commonly used assays: Specific adducts, ^32^P-postlabeling (not chemical-specific), immunoassays (moderate specificity), LC-MS or GC-MS (specific)
| Phosphate adducts | | Longer persistence than DNA base adducts | Endpoint considerations: Challenging direct measurement due to their structural complexity
| Adductomics (DNA) | | | Endpoint considerations: Totality of adducts (untargeted)
Protein adducts | Serum specific adducts Albumin Hemoglobin Most common is cysteine, but also aspartate, histidine, valine, tryptophan, glutamate, and lysine | Exposed humans or animals: Blood, RBC Ex vivo, in vitro, cell-free | Week(s)-month(s) (longer for hemoglobin) | Endpoint considerations: • Relative hardness (polarizability) of low to high: thiol group of cysteine, at a sulfur atom of methionine, primary amino groups (e.g., lysine, arginine), secondary amino groups of histidine • In humans, substance-specific hemoglobin and albumin adducts may also serve as exposure biomarkers. • Animal studies indicate that initial levels of DNA and protein adducts in animals administered a genotoxic agent are proportional to one another. Common specific assays: Immunoassay, fluorescence (e.g., laser-induced fluorescence), LC-MS, GC-MS
| Adductomics (protein) | Exposed humans | | Endpoint considerations: Untargeted approach, usually for human serum albumin and hemoglobin Commonly used assay: LC-MS
| Chemoproteomics | In situ, in vitro, ex vivo Exposed humans or animals | | Endpoint considerations: Activity-based protein profiling using various probes
Protein modification | Protein thiol groups and other nucleophilic sites: Glutathione depletion | Rat or human liver microsomes | | Endpoint considerations: Also used as a biomarker of oxidative stress (KCC5)
Electrophilic reactivity | E_LUMO_ or E_HOMO_ Band gap (E_HOMO_ - E_HOMO_) | In silico or in vitro cells | Not relevant
| Chemical reactivity assays | In chemico with reference nucleophiles
| Electrophilicity index | In silico | | Endpoint considerations: Power of a chemical species to accept random numbers of electrons

Sources: (Carlsson et al. 2019; Hwa Yun et al. 2020; La Barbera et al. 2022; LoPachin and Gavin 2016; Ma et al. 2019; Nesnow et al. 1993; Pfohl-Leszkowicz 2008; Poirier 2016; Poirier et al. 2000; Schwöbel et al. 2011; Shalini et al. 2017; Smith et al. 2020; Törnqvist et al. 2002; Veglia et al. 2008).

GC-MS = gas chromatography-mass spectrometry, EHOMO = energy of the highest occupied molecular orbital, ELUMO = energy of the lowest unoccupied molecular orbital, LC-MS = liquid chromatography-mass spectrometry.

We used the term indicators for effects that are not biomarkers per se, such as outcomes.

## D.2 Is Genotoxic (KCC2)

Genotoxicity typically refers to a substance's ability to cause gene mutations, DNA damage, structural chromosome aberrations, and aneuploidy (numerical chromosome aberrations) and is directly linked to carcinogenicity. OECD provides procedures for testing many of these endpoints. Genotoxicity overlaps with KCC1 (is electrophilic [e.g., DNA adducts]), KCC3 (alters DNA repair or causes genomic instability), and KCC5 (induces oxidative stress [e.g., oxidative damage to DNA). Subtypes in Table D-2 are categorized by increasing structure hierarchy, followed by older or less commonly used tests; within each subtype, biomarkers are arranged alphabetically.

Table D-2 Background Information on Common Biomarkers or Indicators of Genotoxicity (KCC2)

Subtype | Biomarkers/Indicators/Assay | Evidence Type: Biospecimen | Persistence/Induction | Comments or Guidance
DNA damage | DNA damage • Comet assays [in vitro and in vivo including specialized lesions] • γH2AX (Phosphorylation of H2AX) • TGx-DNA Damage Induced Transcriptomic Biomarker • Transcription factor p53 activation | Exposed humans or animals: Lymphocytes, exfoliated cells (exposed humans), target tissues In vitro: Various cell lines (e.g., human lymphoblastoid TK6 cells) | Hours | Recommended assay: OECD Test No. 489: In Vivo Mammalian Alkaline Comet Assay • Timing for in vivo comet assay depends on substance-specific metabolism and DNA repair kinetics Multiplexed fluorescence staining assays for DNA damage
Mutations | All biomarkers | | | Endpoint association with cancer: • Ames-positive and in vivo MN-positive chemicals are strong predictors of carcinogenicity. • Chemical-specific mutational spectra observed in cancers.
| Bacterial reverse mutation tests • Base-pair substitution/frame shifts | In vitro: Bacteria (Ames) In vitro: Panel of Salmonella and some E. coli strains; positive result in any strain is relevant Exposed humans: Can use urine to test mutagenicity | Persistent (cell life) | Recommended assay: OECD Test No. 471: Bacterial Reverse Mutation Test
| Forward gene mutations: Reporter locus • HPRT • XPRT • tk (broader range) | In vitro Various cell lines (e.g., Chinese hamster As52) In vitro: Mouse lymphoma assay; TK6 cells | Persistent (cell life) Days to weeks Days | Recommended assay: OECD Test No. 476: In Vitro Mammalian Cell Gene Mutation Tests Using the HPRT and XPRT Genes Recommended assay: OECD Test No. 490: In Vitro Mammalian Cell Gene Mutation Tests Using the Thymidine Kinase Gene
| Glycophorin A HPRT mutational frequency | Exposed humans: blood (erythrocytes) Exposed humans (usually): lymphocytes
| Pig-a gene mutation assay | Exposed humans or animals: Blood (erythrocytes) | Persistent (cell life) | Recommended assay: OECD Test No. 470: Mammalian Erythrocyte Pig-a Gene Mutation Assay
| Somatic or germ cell transgenic rodent assays (e.g., Big Blue mouse or rat) | Exposed rodents: almost every organ or tissue | Days (fast dividing) to weeks (slow dividing) | Recommended assay: OECD Test No. 488: Transgenic Rodent Somatic and Germ Cell Gene Mutation Assays
| Ultra-accurate, error-corrected DNA sequencing approaches (not locus-dependent) | In vitro, exposed animals or humans (blood, cells from urine) | Persistent | Commonly used assays: Duplex sequencing, PacBio HiFi sequencing
Chromosomal damage | Chromosomal aberration (structural) [CA] test with or without FIS) | In vitro or ex vivo: Primary cells or cell lines (e.g., lymphocytes) | Persistent (cell life) | Endpoint association with cancer: MN and CA associated with increased cancer risk in prospective cohort studies Recommended assay: OECD Test No. 473: In Vitro Mammalian Chromosomal Aberration Test
| | Exposed humans or animals: bone marrow, whole blood, lymphocytes, exfoliated cells (humans), target tissues | Days to weeks | Recommended assay: OECD Test No. 475: Mammalian Bone Marrow Chromosomal Aberration Test
| Micronucleus [MN] test: Structural and numerical (CBMN, centromere/kinetochore analysis) | In vitro cells Exposed humans or animals: Erythrocytes and other proliferating cells | Days to weeks | Recommended assay: OECD Test No. 487: In Vitro Mammalian Cell Micronucleus Test Recommended assay: OECD Test No. 474: Mammalian Erythrocyte Micronucleus Test
Older tests or less common: Mutations | Rodent dominant lethal Sex-linked recessive lethal (drosophila), assays in yeast | Exposed animals Exposed non-mammalian systems | | Recommended assay: OECD Test No. 478 Endpoint considerations: No longer recommended; good indicators of genotoxicity; however, its relevance to humans is unclear
Older tests or less common: Chromatid damage | Sister-chromatid exchanges | In vitro Ex vivo: Cells from exposed humans/animals | | Endpoint considerations: No longer recommended; findings do not correlate well with rodent carcinogenicity

Sources: (Battershill et al. 2008; Bonassi et al. 2011; Eastmond et al. 2009; European Commission 2008; Kirkland et al. 2005; Ladeira and Smajdova 2017; Li et al. 2019; Myers and Grant 2014; Norppa et al. 2006; Olsen et al. 1996; OECD 2015; 2016a; 2016b; 2016c; 2016d; 2016e; 2016f; 2016g; 2020; 2022; Smith et al. 2020).

CBMN = cytokinesis-blocked micronucleus, FISH = fluorescence in situ hybridization, HPRT = hypoxanthine-guanine phosphoribosyl transferase, MN = micronucleus, OECD = Organisation for Economic Co-operation and Development, TK = thymidine kinase, XRPT = xanthine phosphoribosyl transferase.

We used the term indicators for effects that are not biomarkers per se, such as outcomes.

## D.3 Alters DNA Repair or Causes Genomic Instability (KCC3)

Genome integrity includes (1) nucleotide instability (NIN) or DNA repair capacity (DRC), (2) microsatellite instability (MSI or MIN), and (3) Chromosomal instability (CIN) and chromosome structure instability (CSI). It is maintained by DNA damage response pathways that include the following five major DNA repair pathways: (1) base excision repair (BER), (2) nucleotide excision repair (NER), (3) mismatch repair (MMR), (4) homologous recombination, and (5) nonhomologous end joining (Chatterjee and Walker 2017). Nucleotide instability results from replication errors and impairment of BER and NER pathways in nuclear DNA or BER in mitochondrial DNA. Within the DRC subtype, direct biomarkers of DNA damage (related to repair) are presented first, organized alphabetically, followed by measures of enzyme activities.

Table D-3 Background Information on Common Biomarkers or Indicators of DNA Repair or Genomic Instability (KCC3)

Subtype | Biomarkers/Indicators | Evidence Type: Biospecimen | Comments or Guidance
DNA repair capacity (DRC) or nucleotide instability (NIN) | All | | Endpoint considerations: NIN results from replication errors and impairment of BER and NER pathways in nuclear DNA, or BER in mitochondrial DNA. Endpoint association with cancer: Inherited DNA repair-deficiency syndromes are linked to an increased risk of cancer. Lower DRC is linked to elevated cancer risk for all cancer combined and several specific cancer types (meta-analyses) using various assays.
| Comet assay: DNA damage | In vitro (kinetics): cells treated at various times | Assay considerations: • OECD recommends over UDS, OECD TG 489 (in vivo comet assay) • Assays can be done in vivo but are usually not done due to expense (multiple time points)
| Comet: in vitro DNA repair assay | Exposed humans or animals: Tissues and lymphocytes Possible in vitro | Endpoint consideration: Extracts of tissues/cells from exposed animals/humans mixed in vitro with substrate DNA (e.g., from cells exposed to certain agents); artificially induce BER- or NER-related lesions
| Challenge assay | Ex vivo: lymphocytes from humans | Endpoint consideration: DNA strand breaks (comet) or chromosome aberrations after treatment with IR, UVR, or other agents; validated for its sensitivity and specificity
| γH2AX assay: double-strand breaks and repair proteins | Ex vivo: lymphocytes from humans Exposed humans | Endpoint association with cancer: Increased γH2AX foci were associated with significantly increased risks for cancer.
| Host cell reactivation: site-specific DNA lesions | Ex vivo: lymphocytes from humans | Assay considerations: • Newer test: fluorescence-based/multiplex; different types of DNA damage • Older tests require a significant amount of blood and have high background rates
| Topoisomerases (I and II) activity | In vitro: Cell extracts (nuclear and cytosolic) from cultured cells, or cell or tissue extracts from exposed humans or animals | Endpoint association with cancer: Topoisomerase inhibitors are anti-cancer drugs, and some are also human carcinogens.
| UDS | In vitro | Assay considerations: • Low sensitivity: OECD TG 482 (retired in 2014)
| | Exposed animals: mammalian liver | • Low sensitivity for some types of chemicals; OECD TG 486
Microsatellite instability (MSI or MIN) | MSI markers | Usually in tumors | Endpoint association with cancer: Random insertion and expansion of microsatellites can lead to a hypermutable phenotype. Result from defects in MMR and are features of several types of MMR-deficient cancers. Assay considerations: • Commonly used assays: NGS, PCR with HPLC or fluorescence or radioactive probes, and gel or capillary electrophoresis • NGS allows for a greater number of MSI markers to be analyzed.
Chromosomal instability (CIN) and chromosome structure instability (CSI) | Inter-/intra-chromosomal translocations: spectral karyotyping, WGS/NGS Copy number variations: duplications, deletions, amplifications, and insertions, WGS/NGS, aCGH | Exposed humans or animals, in vitro: Karyotyping: single-cell level Exposed humans or animals, in vitro: WGS/NGS: single- or multi-cell Exposed humans or animals, in vitro: Other assays: usually multi-cell Cells: in vitro or from exposed humans or animals DNA from cancer or normal cells (controls) | Endpoint considerations: Rate of gain or loss of segmental and whole chromosomes during cell division; consequences are aneuploidy and LOH Endpoint association with cancer: • CIN is characteristic of 90% of solid tumors and is associated with increased tumor progression and invasiveness. • Inherited CSI and CIN syndromes are associated with increased cancer risk in humans.

Sources: (Azqueta et al. 2014; Baudrin et al. 2018; Figueroa-González and Pérez-Plasencia 2017; Gantchev et al. 2022; Kaina et al. 2018; Nitiss et al. 2012; OECD 2016f; Owiti et al. 2021; Smith et al. 2020; Thompson and Compton 2011; Wu et al. 2022).

aCGH = array comparative genomic hybridization, BER = base excision repair, CIN = chromosomal instability, CSI = chromosome structure instability, DRC = DNA repair capacity, HPLC = high preference liquid chromatography, IR = ionizing radiation, LOH = Loss of heterozygosity, MMR = mismatch repair, MIN = microsatellite instability, NER = nucleotide excision repair, OECD = Organisation for Economic Co-operation and Development, WGS/NGS = whole genome sequencing/next-generation sequencing, XRCC1 = X-ray repair cross complementing 1, UDS = unscheduled DNA synthesis, UVR = ultraviolet radiation.

We used the term indicators for effects that are not biomarkers per se, such as outcomes.

## D.4 Induces Epigenetic Alterations (KCC4)

Epigenetics encompasses various mechanisms that regulate gene expression without altering the underlying DNA sequence and plays a key role in normal mammalian development (Marczylo et al. 2016). The epigenome is a term that encompasses the complete epigenetic status of a cell at any given time. Environmentally-induced epigenetic toxicity is a rapidly emerging field and there is increasing evidence that epigenetic alterations play an important role in chemically-induced carcinogenesis (Chappell et al. 2016). The following sections provide guidance on rating the confidence in the body of evidence that a substance induces epigenetic changes and that these changes are key mechanistic events leading to carcinogenicity. Subtypes are organized by increasing structure hierarchy.

Table D-4 Background Information on Common Biomarkers or Indicators of Epigenetic Effects (KCC4)

Subtype | Biomarkers/Indicators | Evidence Type: Biospecimen | Persistence | Comments or Guidance
DNA methylation: 5-methylcytosine (5mC), Promoters/CpG islands | Gene-specific: Clock genes or genes related to cancer mechanisms or pathways (e.g., tumor suppressor, DNA repair, immune function, metabolism, etc.) | Exposed humans or animals: Body fluids or cells (e.g., blood, sputum, urine, buccal cells), dried blood, fresh or formalin-fixed tissues, tissue (tumor or non-tumor) circulating cell-free DNA In vitro | Rapid Potentially reversible and can be inherited Stable | Endpoint association with cancer: Biological age can be assessed by measuring methylation at selected CpG sites in clock genes. Accelerated epigenetic aging measured in WBC is associated with an increased risk of cancer development. Assay considerations: Two-step process: (1) separate methyl from non-methyl (e.g., bisulfite conversion, restriction enzyme) and (2) amplify and measure (e.g., immunostaining, GS-MS, HPLC-MS); Immunoassays are less reliable.
| Global methylation content (level of 5mC relative to total cystine) • Direct measurement • Repeated elements LINE-1 or Alu | Same as above | Same as above | Endpoint association with cancer or considerations: Cancer cells usually exhibit global hypomethylation and promoter hypermethylation at CpG islands of specific genes. • DNA methylation can serve as a biomarker of exposure, biological age (not chronological), cancer risk, or early cancer detection. • Most methylation occurs in repetitive elements (30% of the genome): Line-1/Alu methylation levels in cancerous tissue correlate with global methylation content, and the correlation varies across cell types (usually measured by pyrosequencing). Assay considerations: Same as gene-specific assays
| Genome-scans or panel of genes | | | Commonly used assays: microarrays, next-generation sequencing
Chromatin: histone modifications | Circulating, variants, or post-translational modifications (PTM) usually at the N- and C-terminal tails | Exposed humans or animals: Body fluids or cells (e.g., blood, sputum, urine, buccal cells), dried blood, fresh or formalin-fixed tissues, tissue (tumor or non-tumor) circulating cell-free DNA In vitro | Potentially reversible Lysine methylation and acetylation is reversible | Endpoint association with cancer: Lower or higher levels of PTM are associated with cancer progression and are used in cancer diagnosis.
| Gene-specific: PTM Global genomic content: direct measurement of circulating histones | | | Endpoint considerations: • 4 core histones (H2A, H2B, H3, and H4) and one linker (H1) • Main modifications: acetylation, methylation, phosphorylation, and ubiquitination • Histone methylation occurs at lysine and arginine residues, mainly at H3, followed by H4. Acetylation occurs at lysine residues. Monoubiquitination most commonly occurs on H2A and H2B (MS). • Functional consequence: Transcription (e.g., RNA seq) Assay considerations: • Immunoassays (e.g., ELISA), MS • ChIP qPCR (parallel sequencing technologies coupled to chromatin immunoprecipitation) • Many genes: ChIP-on-Chip (chromatin immunoprecipitation with DNA microarray analysis)
Chromatin accessibility | Tn5 transposase activity | | | Assay considerations: Transposase-accessible chromatin using sequencing (ATAC-seq)

Sources: (Chen et al. 2022; García-Giménez et al. 2017; Mehrmohamadi et al. 2021; Nowacka-Zawisza and Wiśnik 2017; O'Brien et al. 2018; Pajares et al. 2021; Park 2020; Smith et al. 2020; Sun et al. 2019; Vryer and Saffery 2017; Xu and Taylor 2014; Zhao and Shilatifard 2019).

Line-1 = long interspersed numerical elements, Alu are short interspersed numerical elements, ELISA = enzyme-linked immunosorbent assay, WBC = white blood cells

We used the term indicators for effects that are not biomarkers per se, such as outcomes

## D.5 Induces Oxidative Stress (KCC5)

Oxidative stress occurs when there is an imbalance in the redox status within target tissues that favors formation of reactive oxygen species (ROS) and/or reactive nitrogen species (RNS) at the expense of their detoxification (Smith et al. 2020). This imbalance can lead to oxidative damage to DNA, proteins, and lipids and other effects that are directly related to several other KCCs. These include genotoxicity (KCC2), altered DNA repair (KCC3), chronic inflammation (KCC6), and altered cell proliferation, cell death, or nutrient supply (KCC10). Although oxidative stress is a KCC, it is not specific to carcinogens as many non-carcinogens can also induce oxidative stress. Table D-5 generally follows the steps in the biological process of oxidative stress. Within each subtype, biomarkers are generally organized alphabetically.

Table D-5 Background Information on Common Biomarkers or Indicators of Oxidative Stress (KCC5)

Subtype | Biomarkers/Indicators | Evidence Type: Biospecimen | Persistence/ Induction | Comments or Guidance
Oxidants: ROS, RNS, ROM | ROS: H_2_0_2_, OH^-^_,_ ROO^-^, or O_2_^-^ RNS: ONOO^-^, NO_2_ | Cell-free Exposed humans or animals: WBC or other cells, cellular components In vitro (real/time live cells) | Very transient (nsec to sec) to longer lived^a^ | Endpoint considerations: Urinary H_2_O_2_ can be an indicator of whole-body oxidative stress but is confounded by diet Assay considerations: • Measurement instrumentation: electron spin resonance, fluorescent probes, biosensors • Fresh samples are needed; oxidants are unstable • Not recommended for ex vivo tissue homogenates
Oxidants: ROS, RNS, ROM | ROM: ROOH | Exposed humans or animals: Serum/plasma | | Assay considerations: Criticisms of the reliability of the d-ROM test
ROS Modifications: lipid, DNA, protein | All | | | Endpoint considerations: Systemic or tissue-specific oxidative stress
Lipid peroxidation | All | Exposed humans or animals: Body fluid (e.g., urine, serum, plasma), exhaled breath cells, tissues | Minutes to hours | Endpoint considerations: May directly affect the function of target molecules or enzymes or indicate local degrees of oxidative stress
| F2-isoP | | Minutes (serum), hours (urine) | Endpoint association with cancer: Conflicting findings found for breast cancer risk Assay considerations: • IsoP in serum and urine correlate with in vivo oxidative stress in humans and animals (unaffected by diet). • Preferred method and recognized by EFSA.
| MDA/TBARs | | | Endpoint or assay considerations: • MDA/TBARs is a nonspecific biomarker and is susceptible to methodological bias, yet it may have clinical relevance (induces IL-7 producing cells). However, MDA/TBARS is not recommended as the only test of lipid peroxidation. • MDA measured by MS is useful.
| Others: HNE, LOOH, oxLDL | | | Assay considerations: oxLDL recognized by EFSA
Oxidative damage to DNA/RNA | 8-OHdG | Exposed humans or animals: Urine, plasma, serum, tissue | Minutes | Endpoint considerations: Rapidly repaired, usually measured in urine, may serve as an indicator of whole-body oxidative stress Endpoint association with cancer: Some evidence shows that pre-diagnosis frequencies are associated with increased breast cancer risk in postmenopausal women and lung cancer in non-smokers. Often carries greater weight than other biomarkers
| Comet assay modified with lesion-specific repair endonucleases (e.g., OGG1, FPG, Endonuclease III) | Cells (e.g., leukocytes), ex vivo | | Assay considerations: Accepted by EFSA
| Repair enzymes: hOGG APE
| Oxidized guanine/guanosine (OxGua) | Exposed humans or animals: Urine | | Endpoint considerations: OxGua molecules are derived from repair products of the oxidatively generated DNA/RNA lesions, 8-OH-dGuo from DNA, and 8-OHGuo from RNA. Endpoint association with cancer: Pre-diagnosed levels are associated with increased risks of all cancer in non-smokers and possibly men; colorectal cancer in women, non-smokers, and non-obese people; and prostate cancer in non-smokers.
Oxidative stress: Proteins | Carbonylated proteins (CPs), AOPP | Exposed humans or animals: Plasma/serum | Days | Endpoint considerations: • CPs: irreversible; a hallmark of oxidative stress and is biologically significant and clinically relevant
| s-glutathionylation | | | • Prone to methodological artifacts
| 3-nitrotyrosine | | | • Circulating levels of the biomarkers (3-nitrotyrosine) are not equivalent to tissue levels
ROS generating enzymes | MPO, XO | Exposed humans or animals: serum, urine, tissues Ex vivo: neutrophils | Hours | Endpoint considerations: MPO released from neutrophils can also be an indicator of inflammation (KCC6). Endpoint association with cancer: MPO is associated with cancer progression.
Inflammation/oxidative stress biomarkers | COX-2 | Exposed humans or animals: tissues, serum In vitro | Hours to days | Endpoint association with cancer: COX-2 inhibitors can prevent the carcinogenesis of colorectal cancer. Endpoint considerations: It can also be considered as a proinflammatory biomarker (KCC6).
Antioxidant status | Enzymes: SOD, catalase, GST, GPx | Exposed humans or animals: Serum, erythrocytes (catalase) | Minutes
| GSH; Vitamin A, C, E | | Minutes | Assay considerations: Unstable, difficult to analyze
| Nrf2-ARE response pathway | Exposed humans or animals: Leukocytes, tissue | | Assay considerations: Difficult to analyze
| Total antioxidant capacity
Indices | GSH/GSSG ratio Oxy score (damage – protection)

Sources: (Andries et al. 2021; Basu 1998; Brenner et al. 2014; Dai et al. 2009; Frijhoff et al. 2015; Gào et al. 2019; Gryszczyńska et al. 2017; Harris et al. 2008; Ho et al. 2013; Ito et al. 2017; Katerji et al. 2019; Lee et al. 2017; Lim and Thomas 2013; Loft et al. 2013; Loft et al. 2006; Marrocco et al. 2017; Menzel et al. 2021; Murphy et al. 2022; Smith et al. 2020; Tas and Erturk 2017; Valadez-Cosmes et al. 2022).

8-OH-dG = 8-hydroxy-2'-deoxyguanosine, APE = apurinic/apyrimidinic endonuclease, ARE = antioxidant responsive element, AOPP = advanced oxidation protein products, COX-2 = cyclooxygenase-2, FPG = formamidopyrimidine (fapy)-DNA glycosylase, GPx = glutathione peroxidase GSH = glutathione (reduced), GSSG = oxidized glutathione, GST = glutathione S-Transferase, H_2_0_2_ = hydrogen peroxide, HNE = 4-hydroxy-2-nonenal, hOGG = human 8-oxoguanine-DNA-glycosylase, Iso-P = isoprostanes, LOOH = lipid hydroperoxides, oxLDL = oxidized low density lipoproteins, MDA = malondialdehyde, MPO = myeloperoxidase, NO_2_ = nitrogen dioxide, O_2_^-^ = superoxide, OH- = hydroxyl radical, OGG1 = 8-oxoguanine DNA glycosylase, ONOO- = peroxynitrite, RNS = reactive nitrogen species, ROM = reactive oxygen metabolites, ROO- = peroxyl radicals, ROOH = hydroperoxides, ROS = reactive oxygen species, SOD = superoxide dismutase, TBARS = thiobarbituric acid reactive substances, XO = xanthine oxidase, WBC = white blood cells.

We used the term indicators for effects that are not biomarkers per se, such as outcomes.

^a^ Radical electrons/ionization charge species are very transient, others such as H_2_O_2_ are longer lived.

## D.6 Induces Chronic Inflammation (KCC6) or Immune Activation

Many protein biomarkers (e.g., cytokines) can indicate chronic or acute inflammation depending on the exposure conditions. Thus, evidence of chronic or persistent/repeated exposure and/or the timing/duration of response is critical in determining whether the study is measuring chronic inflammation. The RoC review also considers immune activation (e.g., by B-cell antigens) which may be linked to chronic inflammation and both chronic inflammation and dysregulation/persistent immune activation can contribute to the development and progression of cancer. The concept of immunomodulation is part of the 2015 handbook, as recommended by the peer reviewers of that handbook. Table D-6 is organized inflammation-related diseases and pathology, with the remaining subtypes listed alphabetically. Within each subtype, biomarkers are organized alphabetically as well.

Table D-6 Background Information on Common Biomarkers or Indicators of Chronic Inflammation (KCC6) or Immune Activation

Subtype | Biomarkers/Indicators | Evidence Type: Biospecimen | Persistence | Comments or Guidance
Chronic inflammatory diseases (e.g., autoimmune diseases) | Increased risk or incidence of autoimmune diseases that have been linked to cancer | Exposed humans Animal models of autoimmune disease | Months to years
Chronic inflammation with WBC infiltration | Histology Local evidence of infiltration of acute (with evidence of acute exacerbations from repeated exposures) or chronic inflammatory cells | Exposed animals or (possibly) humans: tissue | Timing/ persistence can vary | Endpoint considerations: • Specific cell types can indicate chronic inflammation. Granulocytes (including neutrophils) in tissue indicate acute inflammation. Lymphocytes, plasma cells, and monocytes/macrophages in tissue indicate chronic inflammation. • Pathologists can diagnose acute vs. chronic. • Histological evaluation is limited in exposed humans.
Cytokines and chemokines (some proinflammatory) | Chemokines: MCP-1, MIP-2 Interferon: IFNγ Interleukins^a^: IL-1α, IL-1β, IL-2, IL-6, IL-8, IL-12, IL-15, IL-23 Transforming growth factor: TGFβ Tumor necrosis factor: TNFα | Exposed humans or animals: serum/plasma, tissue, body fluids, exhaled breath Ex vivo, in vitro | Minutes: IL-1β, IL-8, TNFα Hours: IL-6 | Endpoint considerations: • IL-6 is involved in inflammation, autoimmunity, and B-cell malignancies. • The associated cytokine/chemokine receptors are also critical and ideally should be considered together with ligands. Endpoint association with cancer: • Pre-diagnosed elevated circulating (systemic) levels of IL-6 and IL-8 are associated with increased lung cancer risk. Increased IL-6 levels are also associated with all cancers combined and CRC in several studies or meta-analyses. • Experimental (rodent) models for the role of TNFα, TGFβ, IL-1, IL-6, and IL-23 in cancer development or progression.
Acute phase proteins | Amyloid A (serum, SAA) CRP | Ex vivo, in vitro Exposed humans or animals: serum/plasma, tissue | 24 to 48 hr Hours to days | Endpoint considerations: CRP is nonspecific and the most sensitive acute phase protein in humans. Endpoint association with cancer: • Pre-diagnosed elevated circulating CRP is associated with increased cancer incidence/mortality for all cancers combined, and several cancer types, such as lung, CRC, breast, and ovarian. • SAA is associated with an increased risk of several cancers, such as lung and colon, and is correlated with CRP.
| ESR | | Weeks | Endpoint considerations and association with cancer: • ESR is the most widely used laboratory test for evaluating inflammation status in clinical practice, including infection, autoimmunity, and cancer.
Prostaglandin endoperoxide synthase | COX-2 | Exposed humans or animals: tissue, serum In vitro | Hours to days | Endpoint association with cancer: COX-2 inhibitors can prevent the carcinogenesis of colorectal cancer. Endpoint considerations: It can also be considered as an oxidative stress biomarker (KCC5).
Transcription factors | JAK/STAT NF-κβ | Exposed humans or animals: cells/tissue Ex vivo, in vitro | Minutes Hours | Endpoint considerations and association with cancer: NF-κβ activation is essential for inflammation and is activated in several types of cancer.
WBC (circulating) | Increases in total WBC or leukocyte subsets: lymphocytes, monocytes, granulocytes Ratios (NLR, PLR, LMR) and SII Increased bone marrow hematopoiesis | Exposed humans or animals: blood | Days to weeks | Endpoint considerations: • Decreased systemic WBC can also indicate increased inflammation via extravasation into tissue (local inflammation). • In general, lymphocytes are chronic inflammation indicators, and granulocytes are acute inflammation indicators. • NLR represents the imbalance between the innate and adaptive immune response. • SII is based on peripheral lymphocyte, neutrophil, monocyte, and platelet counts. Endpoint association with cancer: • Pre-diagnosed elevated lymphocytes, monocytes, neutrophils, basophils, and NLR are associated with increased lung cancer risk. • Pre-diagnosed elevated leukocytes are associated with an increased risk of all cancers combined, lung cancer, or CRC.
Immune cell activation | B cell stimulation/antigens (antibody production) | Exposed humans or animals: cells/tissue Ex vivo | | Endpoint association with cancer: B-cell stimulation (by the by itself due to autoimmunity or by foreign antigens due to immunosuppression) leads to DNA damage from genomic recombination and mutation during class/isotype switching and somatic hypermutation and possibly increased risk of B-cell lymphoma.
| Macrophage and granulocyte phagocytosis, ROS production | Exposed humans or animals: cells/tissue Ex vivo, in vitro | | Endpoint considerations: • ROS from immune cells contribute to oxidative stress (immune-regulated ROS can be considered under inflammation or oxidative stress- KCC5).
| | | | • Persistent immune cell activation can be a driver of chronic proinflammatory responses. • It can be difficult to definitively determine if evidence/endpoints of immune activation are linked to chronic inflammation.

Sources: (Allin et al. 2016; Brenner et al. 2017; Brenner et al. 2014; Chauhan and Trivedi 2020; Germano et al. 2008; He et al. 2022; Hirano 2021; Ji et al. 2022; Kakourou et al. 2015; Kang et al. 2019; Liu et al. 2021; Michels et al. 2021; Puar et al. 2018; Qian et al. 2019; Smith et al. 2020; Van Hemelrijck et al. 2011; Wong et al. 2020; Zhou et al. 2012; Zhou et al. 2014; Zhu et al. 2022).

COX-2 = cyclooxygenase-2, CRP = C-reactive protein, ESR = erythrocyte sedimentation rate, JAK/STAT = Janus kinase/signal transducers and activators of transcription, INFγ = interferon gamma, LMR = lymphocyte to monocyte ratio, MCP-1 = macrophage chemoattractant protein-1, MCP-2 = macrophage chemoattractant protein-2, NF-κβ = nuclear factor kappa-light-chain-enhancer of activated B cells (NF-κβ), NLR = neutrophil to lymphocyte ratio, PLR = platelet to lymphocyte ratio, ROS = reactive oxygen species, SAA = serum amyloid A, SII = systemic immune-inflammation index, TGFβ = transforming growth factor beta, TNFα = tumor necrosis factor alpha, WBC = white blood cell.

We used the term indicators for effects that are not biomarkers per se, such as outcomes.

^a^ Some interleukins (like IL-8) are considered to be chemokines.

## D.7 Is Immunosuppressive (KCC7)

Immunosuppression is characterized by a reduction in the capacity of the immune system to respond effectively to foreign antigens, including surface antigens on tumor cells. Potentially neoplastic cells may escape immune surveillance which facilitates the survival of tumor cells. T cells and natural killer cells are critical components in anti-tumor immunity. Table D-7 prioritizes the most clinically relevant and direct measures of immunosuppression, followed by indirect measures (or subtypes). Biomarkers within each subtype are organized alphabetically.

Table D-7 Background Information on Common Biomarkers or Indicators of Immunosuppression (KCC7)

Subtype or Assay | Biomarkers/Indicators | Evidence type: Biospecimen | Comments or Guidance
Increased infections | Increases in the incidence of opportunistic infections (especially viral) | Exposed humans (observational studies) or animals | Endpoint considerations: Strong evidence for immunosuppression
Immune function (challenge to foreign antigen) | Decreases in primary or secondary antibody response to vaccinations or natural antigens | Exposed humans (controlled clinical or observational studies) or animals | Endpoint considerations: • Strong evidence for immunosuppression but indicator may not be relevant for immunosurveillance and cancer risk. • Not usually conducted in humans because of ethical reasons. • Observational studies may evaluate whether environmental exposure affects vaccination antibody response.
| Decreases in NK function, phagocytosis/bacterial killing by PMNLs, antigen presentation | Exposed humans or animals Ex vivo
Immune function (humoral or cell-mediated immunity) | Decreases in antibody production (e.g., T cell dependent, antigen-specific) including specific subclasses/isotypes, NK or CTL activity, T cell activity | Exposed humans or animals Ex vivo | Endpoint association with cancer: • Impact on CTL or NK activity and memory T cells may be most relevant for cancer (e.g., immunosurveillance) with B cell/antibody production less relevant. • Low CTL activity is associated with increased cancer risk.
Immune components | Cytokines: IL-10, TGFβ | Exposed humans or animals | Endpoint considerations: Not sensitive or predictive alone to predict immunosuppression but may be used to support experimental animal data.
| Immunoglobulins (T cell-dependent or -independent)
| Lymphocyte phenotyping (decreased NK, NKT, CD4+ T, CD8+ T; increased CTLA4+ T, Tregs)
Immune components (hematology) | Altered WBC and leukocyte subsets | Exposed humans or animals | Endpoint considerations: Only severe changes are sufficient evidence of immunosuppression.
Immune organs (histopathology and organ weights) | Lymph node or splenic germinal centers, bone marrow suppression of hematopoiesis | Exposed humans or animals | Endpoint considerations: • Reduced organ weight may be secondary to general toxicity or stress. • Extensive histopathology may support the weight of evidence for immunosuppression. • Evaluation is limited in exposed humans.

Source: (Imai et al. 2000; IPCS 2012; Lebrec et al. 2016; Ponce et al. 2014; Sharma et al. 2017; Smith et al. 2020).

CTL = cytotoxic T lymphocyte, NK = natural killer cell, PMNL = polymorphonuclear leukocyte, TGFβ = transforming growth factor beta, WBC = white blood cell.

We used the term indicators for effects that are not biomarkers per se, such as outcomes.

## D.8 Modulates Receptor-mediated Effects (KCC8)

Some receptors promote cell proliferation (e.g., hormone nuclear receptors such as estrogen [ER], androgen [AR], and progesterone [PR]). Activation of the aryl hydrocarbon receptor (AhR) can lead to immunosuppression (KCC7), in addition to effects on cell proliferation and survival (KCC10) (Smith et al. 2020). Table D-8 prioritizes the most relevant and direct measures of receptor-mediated effects, followed by indirect measures (or subtypes). Biomarkers within each subtype are organized alphabetically.

Table D-8 Background Information on Common Biomarkers or Indicators of Receptor-mediated Effects (KCC8)

Subtype | Biomarkers/Indicators | Evidence Type: Biospecimen | Persistence | Comments or Guidance
Receptor-mediated genomic action (NRs, AhR) | All | | | Endpoint considerations: Nuclear and cytosolic receptors are more relevant than peptide-regulated growth factor receptors.
| Activates or antagonizes receptors, e.g., ER, PR, AR, AhR | Cell-free Cell culture (in vitro): including non-cancerous and cancerous, endogenously expressing or transiently/stably transfected Exposed humans or animals | Months | Assay considerations: • Commonly used assays: ER, AR, AhR transactivation assays (OECD TG-455, TG-458, US EPA METHOD 4435, JIS K 0463) • Measures both receptor binding and function
| Interacts with receptors: ER and AR binding | Cell-free In vitro cells (usually human) | Months | Assay considerations: • Recommended assay: OECD TG 493 • Receptor binding-only assays do not indicate downstream effects
Alters hormone/ligand synthesis (levels), distribution, and transport | Binding to enzymes and transport proteins f h | Cell-free In vitro cells (human H295 cancer cells), human recombinant microsomes | Months | Recommended assays: Steroidogenesis with H295R (OECD TG-456), Aromatase assays (US EPA 890.1200/1550), Radioligand binding and displacement (e.g., displacement of 125I-T4)
| Endogenous hormone levels (e.g., E2, T, T4) Sex hormone-binding globulins levels and modulation | Exposed humans or animals: serum/plasma, urine, other fluids, tissue | | Endpoint considerations: Agents that modulate ligand transport, distribution, and clearance can also indirectly modulate receptor-mediated effects. Recommended assays: Usually hormone immunoassays Endpoint association with cancer: • Increased levels of endogenous estrogens and androgens with subsequent increase in receptor-mediated activation is associated with breast cancer risk in pre-and postmenopausal women. • Estrogen (endometrial, ovary, and limited for breast cancer) and estrogen-progestogen menopausal therapy (breast and endometrial cancer), and estrogen-progestogen oral contraceptives (breast, cervical, and liver cancer) are known human carcinogens. • Pre-diagnosed circulating androgens and estrogens are associated with an increased risk of non-serous ovarian cancer in postmenopausal women. • Thyrotropin levels that are suggestive of hyperthyroid function are associated with increased cancer risk, specifically, with an increased risk of lung and prostate cancer.
Alters nuclear receptor expression | ER, PR, AR | Exposed humans or animals: serum/plasma | Months | Recommended assays: Immunohistochemistry or western blotting with animal or human tissue Endpoint association with cancer: The overexpression of ER in benign breast epithelium is associated with estrogen sensitivity and breast cancer risk.

Sources: (Diel et al. 2000; Endogenous Hormones Breast Cancer Collaborative Group et al. 2011; Endogenous Hormones Breast Cancer Collaborative Group et al. 2013; Hellevik et al. 2009; Hogervorst et al. 2013; IARC 2012; 2019; Jacobs et al. 2020; Key et al. 2002; Khan et al. 1998; McIver et al. 2013; Meerts et al. 2000; NTP 2021; Smith et al. 2020; Trabert et al. 2019).

NR = nuclear receptor, AR = androgen receptor, ER = estrogen receptor, PR = progesterone receptor, AhR = aryl hydrocarbon receptor, E2 = 17b-estradiol, OECD = Organisation for Economic Co-operation and Development, T = testosterone, T4 = thyroxine.

We used the term indicators for effects that are not biomarkers per se, such as outcomes.

## D.9 Causes Immortalization (KCC9)

Cancer cells can become immortal by reversing the normal telomere shortening process (which occurs with age) and lengthening their telomeres. Telomere shortening can lead to senescence or apoptosis. Table D-9 prioritizes direct measures of immortalization, followed by indirect measures (or subtypes). Subtypes are organized alphabetically.

Table D-9 Background Information on Common Biomarkers or Indicators of Immortalization (KCC9)

Subtype | Biomarkers/Indicators | Evidence Type: Biospecimen | Induction Period | Comments or Guidance
Cell transformation | Cell foci formation | In vitro: most common, include Syrian Hamster Embryo (SHE) and Balb/c 3T3 cells; others are C3H10T1/2 and Bhas 42 cells Exposed animals: Transfer transformed cells into an immune-deficient host such as nude mice | Weeks to months Months | Endpoint considerations: • Validated testing protocols to detect rodent carcinogens have been established for SHE and Balb/c 3T3 cell transformation assays, with SHE assays being the most reproducible between laboratories. Note that SHE cells are primary cells and less likely to undergo spontaneous transformations, whereas the other cell types noted are immortalized cell lines. • Inactivation of tumor suppressor genes or activation of oncogenes or increases in cyclin D1 expression in foci-derived or other cell assays adds confidence to any positive findings.
| De-differentiation (epithelial-mesenchymal transition) | In vitro: human or animal epithelial cells (e.g., lung, prostate) | Months | • Loss of E-cadherin, increased expression of fibronectin, increased growth in serum-free media
| Increased invasiveness | In vitro: human or animal epithelial cells | Months | • Increased invasiveness into extra cellular matrix or increased colony formation in soft agar
Cellular senescence inhibition | Alterations in senescence biomarkers: beta-galactosidase, cell cycle check-point inhibitors, or tumor suppressor gene expression Continued cell proliferation and inhibition of change to senescent cell phenotype | In vitro: embryonic stem cells, human fibroblasts, and other cell lines Exposed humans or animals: tissue | | Endpoint considerations: Multiple biomarkers increase the validation of whether senescence has occurred or is inhibited (a single biomarker is insufficient).
Stem cell gene alterations | Morphological changes Transcription factors expression: c-Myc, Oct3/4, Klf4, Sox2 Loss of tumor suppressor genes in stem cells: p16, p53, MYC | In vitro: Somatic cells Exposed animals: genetically modified, chimeric mice Exposed humans | | Endpoint considerations: Induced pluripotent stem cells as evidenced by morphological effects (e.g., cell size, cell component ratios, colony ratio) and induction of transcription factors that can reset the somatic cell epigenome
Telomere and telomerase activity | Changes in telomere length (shorter or longer) Telomerase activity | Exposed humans or animals: Whole blood or peripheral blood leukocytes (PBLs), tissue (normal, embryonic) In vivo or ex vivo: Stem cells | Days | Endpoint association with cancer: • Increased telomerase activity is a risk factor for cancer. • Change in telomere length (e.g., shorter or longer) varies with different cancer types. More assay validation and standardization are needed across studies on telomere length. Recommended assays: • Telomerase activity assays: telomere repeat amplification protocols (TRAPs) or detection of telomerase-synthesized DNA; Telomerase activity is not detected in most human somatic cells. • Telomere length assays: quantitative polymerase chain reaction (qPCR) standardization to a single copy gene and may be used in tandem with TRAPs. Endpoint considerations: Telomere length, a marker of biological age, correlates with telomerase activity.

Sources: (Ahmadzai et al. 2012; Axelrad et al. 2013; Chiba et al. 2017; Creton et al. 2012; Dimri et al. 1995; González-Gualda et al. 2021; Mascolo et al. 2018; Masuda et al. 1997; Mender and Shay 2015; Ohnishi et al. 2014; Person et al. 2013; Schmidt and Plath 2012; Smith et al. 2020; Tokar et al. 2005; Tokar et al. 2010; Walcher et al. 2020; Wentzensen et al. 2011; Zhang et al. 2017).

We used the term indicators for effects that are not biomarkers per se, such as outcomes.

## D.10 Alters Cell Proliferation, Cell Death, or Nutrient Supply (KCC10)

The ability of carcinogens to modify cell proliferation, cell death, and nutrient supply is central to their role in cancer development. By disrupting these essential processes, carcinogens create an environment where cells can grow uncontrollably, evade pathways that prevent tumor formation, and sustain their growth through enhanced nutrient and oxygen supply. Several of these biomarkers measure tumor progression. This table is mainly based on Smith et al. (2020) and will be expanded as part of our periodic updates based on lessons learned. Subtypes are organized based on the definition of the KCC. Within each subtype, biomarkers are organized alphabetically.

Table D-10 Background Information on Common Biomarkers or Indicators of Cell Proliferation, Cell Death, or Nutrient Supply (KCC10)

Subtype | Biomarkers/Indicators | Evidence Type: Biospecimen | Comments or Guidance
Sustained cellular proliferation | Cell numbers | Exposed animals or humans, in vitro | Recommended assays: radiolabeled 3H-thymine incorporation and non-radioactive bromodeoxyuridine (BrdU) immunoassay
| Colony formation | In vitro
| DNA synthesis during S phase | In vitro Exposed animals Ex vivo: human tumor tissue
| Hyperplasia | Ex vivo: animal and human tissue or biopsies
| Metabolic activity | In vitro
| Nuclear antigen (e.g., proliferating cell nuclear antigen or cell cycle biomarkers) | In vitro Exposed humans or animals
Evasion or reduction of apoptosis | Apoptosis biomarkers: Expression of pro- and anti-apoptotic factors (e.g., caspase-3) | In vitro Exposed humans or animals: Tissue (including tumor) and blood | Assay considerations: Detection of apoptosis in vivo is challenging because of the short half-life of apoptotic cells, thus timing is critical. Recommended assays: Immunoassays, DNA arrays
| DNA fragmentation Loss of phospholipid asymmetry | In vitro | Recommended assay: TUNEL Recommended assay: Annexin V with nuclear staining
Pathogenic (sustained) angiogenesis and neo-angiogenesis | Endothelial cell activation: proliferation, migration, and differentiation | In vitro or ex vivo: endothelial cells, umbilical vein endothelial cells, endothelial cell spheroid, stem cells, | Recommended migration and invasion assays: Cell culture wound closure, trans-well migration and invasion assays • Other endothelial cell angiogenic assays: endothelial cell proliferation in response to stimulus (e.g., VEGF, PDGF, bFGF); • chemotaxis in response to attractant gradient; • haptotaxis or tubular differentiation on matrix proteins; • proteolytic enzyme production; • tube-forming assays (e.g., on Matrigel).
| Endothelial sprouting, migration, and differentiation into capillaries | Ex vivo: umbilical artery | Recommended assay: Human arterial ring assay
| Vascularity: Active neovascularization | Exposed humans or animals: tissue; ex vivo | Recommended assays: Histological assessment of vessels, increased tumor levels of pro-angiogenic factors for endothelial cell activation (e.g., VEGF, PDGF, bFGF), tissue blood flow rates
| Vascularity: Tumor vascularity | Exposed humans or animals: tumor tissue; ex vivo | Endpoint considerations: Angiogenic antigens (e.g., endogen, nestin)
Glycolytic (Warburg) shift | Cellular respiration | In vitro
| Glucose rate | Exposed humans or animals: tumors | Endpoint association with cancer: Promotes tumorigenesis and malignancy progression; it remains uncertain whether it is a direct cause or a consequence of cancer

Source: (Beresford et al. 2006; Brown et al. 2016; Devic 2016; Eccles et al. 2016; Nishida et al. 2006; Nowak-Sliwinska et al. 2018; Pang et al. 2016; Seano and Primo 2016; Smith et al. 2020; Tozer et al. 2016; Ward et al. 2008; Zippel et al. 2016).

TUNEL = terminal deoxynucleotidyl transferase-mediated dUTP nick end labeling VEGF = vascular endothelial growth factor; PDGF = platelet-derived growth factor; bFGF = basic fibroblast growth factor.

We used the term indicators for effects that are not biomarkers per se, such as outcomes.

## References

Ahmadzai AA, Trevisan J, Fullwood NJ, Carmichael PL, Scott AD, Martin FL. 2012. The Syrian hamster embryo (SHE) assay (pH 6.7): Mechanisms of cell transformation and application of vibrational spectroscopy to objectively score endpoint alterations. Mutagenesis. 27(3):257–266. 10.1093/mutage/ger086 22147764
Allin KH, Bojesen SE, Nordestgaard BG. 2016. Inflammatory biomarkers and risk of cancer in 84,000 individuals from the general population. Int J Cancer. 139(7):1493–1500. 10.1002/ijc.30194 27194008
Andries A, Rozenski J, Vermeersch P, Mekahli D, Van Schepdael A. 2021. Recent progress in the LC-MS/MS analysis of oxidative stress biomarkers. Electrophoresis. 42(4):402–428. 10.1002/elps.202000208 33280143
Axelrad MD, Budagov T, Atzmon G. 2013. Telomere length and telomerase activity; a yin and yang of cell senescence. J Vis Exp. (75):e50246. 23728273
Azqueta A, Slyskova J, Langie SAS, O’Neill Gaivão I, Collins A. 2014. Comet assay to measure DNA repair: Approach and applications. Front Genet. 5:288. 10.3389/fgene.2014.00288 25202323
Basu S. 1998. Metabolism of 8-iso-prostaglandin F_2α_. FEBS Lett. 428(1-2):32–36. 10.1016/S0014-5793(98)00481-5 9645469
Battershill JM, Burnett K, Bull S. 2008. Factors affecting the incidence of genotoxicity biomarkers in peripheral blood lymphocytes: Impact on design of biomonitoring studies. Mutagenesis. 23(6):423–437. 10.1093/mutage/gen040 18678752
Baudrin LG, Deleuze JF, How-Kit A. 2018. Molecular and computational methods for the detection of microsatellite instability in cancer. Front Oncol. 8:621. 10.3389/fonc.2018.00621 30631754
Beresford MJ, Wilson GD, Makris A. 2006. Measuring proliferation in breast cancer: Practicalities and applications. Breast Cancer Res. 8(6):216. 10.1186/bcr1618 17164010
Bonassi S, El-Zein R, Bolognesi C, Fenech M. 2011. Micronuclei frequency in peripheral blood lymphocytes and cancer risk: Evidence from human studies. Mutagenesis. 26(1):93–100. 10.1093/mutage/geq075 21164188
Brenner DR, Fanidi A, Grankvist K, Muller DC, Brennan P, Manjer J, Byrnes G, Hodge A, Severi G, Giles GG, et al. 2017. Inflammatory cytokines and lung cancer risk in 3 prospective studies. Am J Epidemiol. 185(2):86–95. 10.1093/aje/kww159 27998891
Brenner DR, Scherer D, Muir K, Schildkraut J, Boffetta P, Spitz MR, Le Marchand L, Chan AT, Goode EL, Ulrich CM, et al. 2014. A review of the application of inflammatory biomarkers in epidemiologic cancer research. Cancer Epidemiol Biomarkers Prev. 23(9):1729–1751. 10.1158/1055-9965.EPI-14-0064 24962838
Brown RM, Meah CJ, Heath VL, Styles IB, Bicknell R. 2016. Tube-forming assays. In: Martin SG, Hewett PW, editors. Angiogenesis Protocols. 3rd ed. New York, NY: Humana Press. p. 149-157. 10.1007/978-1-4939-3628-1_9
Carlsson H, Rappaport SM, Törnqvist M. 2019. Protein adductomics: Methodologies for untargeted screening of adducts to serum albumin and hemoglobin in human blood samples. High Throughput. 8(1):6. 10.3390/ht8010006 30857166
Chappell G, Pogribny IP, Guyton KZ, Rusyn I. 2016. Epigenetic alterations induced by genotoxic occupational and environmental human chemical carcinogens: A systematic literature review. Mutat Res Rev Mutat Res. 768:27–45. 10.1016/j.mrrev.2016.03.004 27234561
Chatterjee N, Walker GC. 2017. Mechanisms of DNA damage, repair, and mutagenesis. Environ Mol Mutagen. 58(5):235–263. 10.1002/em.22087 28485537
Chauhan R, Trivedi V. 2020. Inflammatory markers in cancer: Potential resources. Front Biosci (Schol Ed). 12(1):1–24. 10.2741/s537 31585862
Chen L, Ganz PA, Sehl ME. 2022. DNA methylation, aging, and cancer risk: A mini-review. Front Bioinform. 2:847629. 10.3389/fbinf.2022.847629 36304336
Chiba K, Lorbeer FK, Shain AH, McSwiggen DT, Schruf E, Oh A, Ryu J, Darzacq X, Bastian BC, Hockemeyer D. 2017. Mutations in the promoter of the telomerase gene TERT contribute to tumorigenesis by a two-step mechanism. Science. 357(6358):1416–1420. 10.1126/science.aao0535 28818973
Creton S, Aardema MJ, Carmichael PL, Harvey JS, Martin FL, Newbold RF, O’Donovan MR, Pant K, Poth A, Sakai A, et al. 2012. Cell transformation assays for prediction of carcinogenic potential: State of the science and future research needs. Mutagenesis. 27(1):93–101. 10.1093/mutage/ger053 21852270
Dai Q, Gao YT, Shu XO, Yang G, Milne G, Cai Q, Wen W, Rothman N, Cai H, Li H, et al. 2009. Oxidative stress, obesity, and breast cancer risk: Results from the Shanghai Women’s Health Study. J Clin Oncol. 27(15):2482–2488. 10.1200/JCO.2008.19.7970 19380446
Devic S. 2016. Warburg effect - a consequence or the cause of carcinogenesis? J Cancer. 7(7):817–822. 10.7150/jca.14274 27162540
Diel P, Schulz T, Smolnikar K, Strunck E, Vollmer G, Michna H. 2000. Ability of xeno- and phytoestrogens to modulate expression of estrogen-sensitive genes in rat uterus: Estrogenicity profiles and uterotropic activity. J Steroid Biochem Mol Biol. 73(1-2):1–10. 10.1016/S0960-0760(00)00051-0 10822019
Dimri GP, Lee X, Basile G, Acosta M, Scott G, Roskelley C, Medrano EE, Linskens M, Rubelj I, Pereira-Smith O, et al. 1995. A biomarker that identifies senescent human cells in culture and in aging skin in vivo. Proc Natl Acad Sci USA. 92(20):9363–9367. 10.1073/pnas.92.20.9363 7568133
Eastmond DA, Hartwig A, Anderson D, Anwar WA, Cimino MC, Dobrev I, Douglas GR, Nohmi T, Phillips DH, Vickers C. 2009. Mutagenicity testing for chemical risk assessment: Update of the WHO/IPCS Harmonized Scheme. Mutagenesis. 24(4):341–349. 10.1093/mutage/gep014 19535363
Eccles SA, Court W, Patterson L. 2016. In vitro assays for endothelial cell functions required for angiogenesis: Proliferation, motility, tubular differentiation, and matrix proteolysis. In: Martin SG, Hewett PW, editors. Angiogenesis Protocols. 3rd ed. New York, NY: Humana Press. p. 121-147. 10.1007/978-1-4939-3628-1_8
Endogenous Hormones Breast Cancer Collaborative Group, Key TJ, Appleby PN, Reeves GK, Roddam AW, Helzlsouer KJ, Alberg AJ, Rollison DE, Dorgan JF, Brinton LA, . 2011. Circulating sex hormones and breast cancer risk factors in postmenopausal women: Reanalysis of 13 studies. Br J Cancer. 105(5):709–722. 10.1038/bjc.2011.254 21772329
Endogenous Hormones Breast Cancer Collaborative Group, Key TJ, Appleby PN, Reeves GK, Travis RC, Alberg AJ, Barricarte A, Berrino F, Krogh V, Sieri S, . 2013. Sex hormones and risk of breast cancer in premenopausal women: A collaborative reanalysis of individual participant data from seven prospective studies. Lancet Oncol. 14(10):1009–1019. 10.1016/S1470-2045(13)70301-2 23890780
European Commission. 2008. Risk assessment methodologies and approaches for mutagenic and carcinogenic substances. Brussels, Belgium: European Commission, Health and Consumer Protection Directorate-General. https://ec.europa.eu/health/ph_risk/committees/04_scher/docs/scher_o_107.pdf
Figueroa-González G, Pérez-Plasencia C. 2017. Strategies for the evaluation of DNA damage and repair mechanisms in cancer. Oncol Lett. 13(6):3982–3988. 10.3892/ol.2017.6002 28588692
Frijhoff J, Winyard PG, Zarkovic N, Davies SS, Stocker R, Cheng D, Knight AR, Taylor EL, Oettrich J, Ruskovska T, et al. 2015. Clinical relevance of biomarkers of oxidative stress. Antioxid Redox Signal. 23(14):1144–1170. 10.1089/ars.2015.6317 26415143
Gantchev J, Ramchatesingh B, Berman-Rosa M, Sikorski D, Raveendra K, Amar L, Xu HH, Villarreal AM, Ordaz DJG, Litvinov IV. 2022. Tools used to assay genomic instability in cancers and cancer meiomitosis. J Cell Commun Signal. 16(2):159–177. 10.1007/s12079-021-00661-z 34841477
Gào X, Holleczek B, Cuk K, Zhang Y, Anusruti A, Xuan Y, Xu Y, Brenner H, Schöttker B. 2019. Investigation on potential associations of oxidatively generated DNA/RNA damage with lung, colorectal, breast, prostate and total cancer incidence. Sci Rep. 9(1):7109. 10.1038/s41598-019-42596-x 31068619
García-Giménez JL, Seco-Cervera M, Tollefsbol TO, Romá-Mateo C, Peiró-Chova L, Lapunzina P, Pallardó FV. 2017. Epigenetic biomarkers: Current strategies and future challenges for their use in the clinical laboratory. Crit Rev Clin Lab Sci. 54(7-8):529–550. 10.1080/10408363.2017.1410520 29226748
Germano G, Allavena P, Mantovani A. 2008. Cytokines as a key component of cancer-related inflammation. Cytokine. 43(3):374–379. 10.1016/j.cyto.2008.07.014 18701317
González-Gualda E, Baker AG, Fruk L, Muñoz-Espín D. 2021. A guide to assessing cellular senescence in vitro and in vivo. FEBS J. 288(1):56–80. 10.1111/febs.15570 32961620
Gryszczyńska B, Formanowicz D, Budzyń M, Wanic-Kossowska M, Pawliczak E, Formanowicz P, Majewski W, Strzyżewski KW, Kasprzak MP, Iskra M. 2017. Advanced oxidation protein products and carbonylated proteins as biomarkers of oxidative stress in selected atherosclerosis-mediated diseases. BioMed Res Int. 10.1155/2017/4975264 28884122
Harris RE, Beebe-Donk J, Alshafie GA. 2008. Similar reductions in the risk of human colon cancer by selective and nonselective cyclooxygenase-2 (COX-2) inhibitors. BMC Cancer. 8:237. 10.1186/1471-2407-8-237 18702823
He MM, Lo CH, Wang K, Polychronidis G, Wang L, Zhong R, Knudsen MD, Fang Z, Song M. 2022. Immune-mediated diseases associated with cancer risks. JAMA Oncol. 8(2):209–219. 10.1001/jamaoncol.2021.5680 34854871
Hellevik AI, Asvold BO, Bjøro T, Romundstad PR, Nilsen TIL, Vatten LJ. 2009. Thyroid function and cancer risk: A prospective population study. Cancer Epidemiol Biomarkers Prev. 18(2):570–574. 10.1158/1055-9965.EPI-08-0911 19155436
Hirano T. 2021. IL-6 in inflammation, autoimmunity and cancer. Int Immunol. 33(3):127–148. 10.1093/intimm/dxaa078 33337480
Ho E, Karimi Galougahi K, Liu CC, Bhindi R, Figtree GA. 2013. Biological markers of oxidative stress: Applications to cardiovascular research and practice. Redox Biol. 1(1):483–491. 10.1016/j.redox.2013.07.006 24251116
Hogervorst JG, Fortner RT, Mucci LA, Tworoger SS, Eliassen AH, Hankinson SE, Wilson KM. 2013. Associations between dietary acrylamide intake and plasma sex hormone levels. Cancer Epidemiol Biomarkers Prev. 22(11):2024–2036. 10.1158/1055-9965.EPI-13-0509 23983241
Hwa Yun B, Guo J, Bellamri M, Turesky RJ. 2020. DNA adducts: Formation, biological effects, and new biospecimens for mass spectrometric measurements in humans. Mass Spectrom Rev. 39(1-2):55–82. 10.1002/mas.21570 29889312
Imai K, Matsuyama S, Miyake S, Suga K, Nakachi K. 2000. Natural cytotoxic activity of peripheral-blood lymphocytes and cancer incidence: An 11-year follow-up study of a general population. Lancet. 356(9244):1795–1799. 10.1016/S0140-6736(00)03231-1 11117911
International Agency for Research on Cancer (IARC). 2012. Pharmaceuticals. (IARC monographs on the evaluation of carcinogenic risks to humans; vol. 100A). Lyon, France: International Agency for Research on Cancer. https://publications.iarc.fr/118
International Agency for Research on Cancer (IARC). 2019. Tumour site concordance and mechanisms of carcinogenesis. Baan RA, Stewart BW, Straif K, editors. Lyon, France: International Agency for Research on Cancer. https://publications.iarc.fr/Book-And-Report-Series/Iarc-Scientific-Publications/Tumour-Site-Concordance-And-Mechanisms-Of-Carcinogenesis-2019
International Programme on Chemical Safety (IPCS). 2012. Guidance for immunotoxicity risk assessment for chemicals. Geneva, Switzerland: World Health Organization. Harmonization Project Document No. 10. https://iris.who.int/handle/10665/330098
Ito F, Ito T, Suzuki C, Yahata T, Ikeda K, Hamaoka K. 2017. The application of a modified d-ROMs test for measurement of oxidative stress and oxidized high-density lipoprotein. Int J Mol Sci. 18(2):454. 10.3390/ijms18020454 28230785
Jacobs MN, Colacci A, Corvi R, Vaccari M, Aguila MC, Corvaro M, Delrue N, Desaulniers D, Ertych N, Jacobs A, et al. 2020. Chemical carcinogen safety testing: OECD expert group international consensus on the development of an integrated approach for the testing and assessment of chemical non-genotoxic carcinogens. Arch Toxicol. 94(8):2899–2923. 10.1007/s00204-020-02784-5 32594184
Ji M, Du L, Ma Z, Xie J, Huang Y, Wei X, Jiang X, Xu J, Yin R, Wang Y, et al. 2022. Circulating C-reactive protein increases lung cancer risk: Results from a prospective cohort of UK Biobank. Int J Cancer. 150(1):47–55. 10.1002/ijc.33780 34449869
Kaina B, Izzotti A, Xu J, Christmann M, Pulliero A, Zhao X, Dobreanu M, Au WW. 2018. Inherent and toxicant-provoked reduction in DNA repair capacity: A key mechanism for personalized risk assessment, cancer prevention and intervention, and response to therapy. Int J Hyg Environ Health. 221(7):993–1006. 10.1016/j.ijheh.2018.07.003 30041861
Kakourou A, Koutsioumpa C, Lopez DS, Hoffman-Bolton J, Bradwin G, Rifai N, Helzlsouer KJ, Platz EA, Tsilidis KK. 2015. Interleukin-6 and risk of colorectal cancer: Results from the CLUE II cohort and a meta-analysis of prospective studies. Cancer Causes Control. 26(10):1449–1460. 10.1007/s10552-015-0641-1 26220152
Kang J, Chang Y, Ahn J, Oh S, Koo DH, Lee YG, Shin H, Ryu S. 2019. Neutrophil-to-lymphocyte ratio and risk of lung cancer mortality in a low-risk population: A cohort study. Int J Cancer. 145(12):3267–3275. 10.1002/ijc.32640 31454064
Katerji M, Filippova M, Duerksen-Hughes P. 2019. Approaches and methods to measure oxidative stress in clinical samples: Research applications in the cancer field. Oxid Med Cell Longev. 10.1155/2019/1279250 30992736
Key T, Appleby P, Barnes I, Reeves G, Endogenous Hormones Breast Cancer Collaborative Group. 2002. Endogenous sex hormones and breast cancer in postmenopausal women: Reanalysis of nine prospective studies. J Natl Cancer Inst. 94(8):606–616. 10.1093/jnci/94.8.606 11959894
Khan SA, Rogers MA, Khurana KK, Meguid MM, Numann PJ. 1998. Estrogen receptor expression in benign breast epithelium and breast cancer risk. J Natl Cancer Inst. 90(1):37–42. 10.1093/jnci/90.1.37 9428781
Kirkland D, Aardema M, Henderson L, Müller L. 2005. Evaluation of the ability of a battery of three in vitro genotoxicity tests to discriminate rodent carcinogens and non-carcinogens: I. Sensitivity, specificity and relative predictivity. Mutat Res. 584(1-2):1–256. 10.1016/j.mrgentox.2005.02.004 15979392
La Barbera G, Nommesen KD, Cuparencu C, Stanstrup J, Dragsted LO. 2022. A comprehensive database for DNA adductomics. Front Chem. 10:908572. 10.3389/fchem.2022.908572 35692690
Ladeira C, Smajdova L. 2017. The use of genotoxicity biomarkers in molecular epidemiology: Applications in environmental, occupational and dietary studies. AIMS Genet. 4(3):166–191. 10.3934/genet.2017.3.166 31435507
Lebrec H, Brennan FR, Haggerty H, Herzyk D, Kamperschroer C, Maier CC, Ponce R, Preston BD, Weinstock D, Mellon RD. 2016. HESI/FDA workshop on immunomodulators and cancer risk assessment: Building blocks for a weight-of-evidence approach. Regul Toxicol Pharmacol. 75:72–80. 10.1016/j.yrtph.2015.12.018 26743742
Lee JD, Cai Q, Shu XO, Nechuta SJ. 2017. The role of biomarkers of oxidative stress in breast cancer risk and prognosis: A systematic review of the epidemiologic literature. J Womens Health (Larchmt). 26(5):467–482. 10.1089/jwh.2016.5973 28151039
Li HH, Yauk CL, Chen R, Hyduke DR, Williams A, Frötschl R, Ellinger-Ziegelbauer H, Pettit S, Aubrecht J, Fornace AJ Jr. 2019. TGx-DDI, a transcriptomic biomarker for genotoxicity hazard assessment of pharmaceuticals and environmental chemicals. Front Big Data. 2:36. 10.3389/fdata.2019.00036 33693359
Lim MY, Thomas PS. 2013. Biomarkers in exhaled breath condensate and serum of chronic obstructive pulmonary disease and non-small-cell lung cancer. Int J Chronic Dis. 10.1155/2013/578613 26464846
Liu C, Chu D, Kalantar-Zadeh K, George J, Young HA, Liu G. 2021. Cytokines: From clinical significance to quantification. Adv Sci (Weinh). 8(15):e2004433. 10.1002/advs.202004433 34114369
Loft S, Olsen A, Møller P, Poulsen HE, Tjønneland A. 2013. Association between 8-oxo-7,8-dihydro-2′-deoxyguanosine excretion and risk of postmenopausal breast cancer: Nested case-control study. Cancer Epidemiol Biomarkers Prev. 22(7):1289–1296. 10.1158/1055-9965.EPI-13-0229 23658396
Loft S, Svoboda P, Kasai H, Tjønneland A, Vogel U, Møller P, Overvad K, Raaschou-Nielsen O. 2006. Prospective study of 8-oxo-7,8-dihydro-2′-deoxyguanosine excretion and the risk of lung cancer. Carcinogenesis. 27(6):1245–1250. 10.1093/carcin/bgi313 16364924
LoPachin RM, Gavin T. 2016. Reactions of electrophiles with nucleophilic thiolate sites: Relevance to pathophysiological mechanisms and remediation. Free Radic Res. 50(2):195–205. 10.3109/10715762.2015.1094184 26559119
Ma B, Stepanov I, Hecht SS. 2019. Recent studies on DNA adducts resulting from human exposure to tobacco smoke. Toxics. 7(1):16. 10.3390/toxics7010016 30893918
Marczylo EL, Jacobs MN, Gant TW. 2016. Environmentally induced epigenetic toxicity: Potential public health concerns. Crit Rev Toxicol. 46(8):676–700. 10.1080/10408444.2016.1175417 27278298
Marrocco I, Altieri F, Peluso I. 2017. Measurement and clinical significance of biomarkers of oxidative stress in humans. Oxid Med Cell Longev. 10.1155/2017/6501046 28698768
Mascolo MG, Perdichizzi S, Vaccari M, Rotondo F, Zanzi C, Grilli S, Paparella M, Jacobs MN, Colacci A. 2018. The transformics assay: First steps for the development of an integrated approach to investigate the malignant cell transformation in vitro. Carcinogenesis. 39(7):955–967. 10.1093/carcin/bgy037 29554273
Masuda A, Kondo M, Saito T, Yatabe Y, Kobayashi T, Okamoto M, Suyama M, Takahashi T, Takahashi T. 1997. Establishment of human peripheral lung epithelial cell lines (HPL1) retaining differentiated characteristics and responsiveness to epidermal growth factor, hepatocyte growth factor, and transforming growth factor beta1. Cancer Res. 57(21):4898–4904. 9354455
McIver CR, Shaw IC, Gin S, Ellis MJ. 2013. Can thyroid hormone mimics affect thyroid hormone measurement by immunoassay? Clin Biochem. 46(13-14):1302–1304. 10.1016/j.clinbiochem.2013.06.030 23850848
Meerts IATM, van Zanden JJ, Luijks EAC, van Leeuwen-Bol I, Marsh G, Jakobsson E, Bergman A, Brouwer A. 2000. Potent competitive interactions of some brominated flame retardants and related compounds with human transthyretin in vitro. Toxicol Sci. 56(1):95–104. 10.1093/toxsci/56.1.95 10869457
Mehrmohamadi M, Sepehri MH, Nazer N, Norouzi MR. 2021. A comparative overview of epigenomic profiling methods. Front Cell Dev Biol. 9:714687. 10.3389/fcell.2021.714687 34368164
Mender I, Shay JW. 2015. Telomerase Repeated Amplification Protocol (TRAP). Bio Protoc. 5(22):e1657. 27182535
Menzel A, Samouda H, Dohet F, Loap S, Ellulu MS, Bohn T. 2021. Common and novel markers for measuring inflammation and oxidative stress ex vivo in research and clinical practice—Which to use regarding disease outcomes? Antioxidants. 10(3):414. 10.3390/antiox10030414 33803155
Michels N, van Aart C, Morisse J, Mullee A, Huybrechts I. 2021. Chronic inflammation towards cancer incidence: A systematic review and meta-analysis of epidemiological studies. Crit Rev Oncol Hematol. 157:103177. 10.1016/j.critrevonc.2020.103177 33264718
Murphy MP, Bayir H, Belousov V, Chang CJ, Davies KJA, Davies MJ, Dick TP, Finkel T, Forman HJ, Janssen-Heininger Y, et al. 2022. Guidelines for measuring reactive oxygen species and oxidative damage in cells and in vivo. Nat Metab. 4(6):651–662. 10.1038/s42255-022-00591-z 35760871
Myers NT, Grant SG. 2014. The blood-based glycophorin A (GPA) human in vivo somatic mutation assay. In: Keohavong P, Grant SG, editors. Molecular Toxicology Protocols. 2nd ed. Totowa, NJ: Humana Press. p. 223-244. 10.1007/978-1-62703-739-6_18
National Toxicology Program (NTP). 2021. Substance profile: Estrogens, steroidal. In: Report on Carcinogens. 15th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/ntp-other-1003
Nesnow S, Ross J, Nelson G, Holden K, Erexson G, Kligerman A, Gupta RC. 1993. Quantitative and temporal relationships between DNA adduct formation in target and surrogate tissues: Implications for biomonitoring. Environ Health Perspect. 101 Suppl 3:37–42. 8143643
Nishida N, Yano H, Nishida T, Kamura T, Kojiro M. 2006. Angiogenesis in cancer. Vasc Health Risk Manag. 2(3):213–219. https://www.tandfonline.com/doi/full/10.2147/vhrm.s23213. 10.2147/vhrm.2006.2.3.213 17326328
Nitiss JL, Soans E, Rogojina A, Seth A, Mishina M. 2012. Topoisomerase assays. Curr Protoc Pharmacol. 57:3.3.1-3.3.27. 10.1002/0471141755.ph0303s57
Norppa H, Bonassi S, Hansteen IL, Hagmar L, Strömberg U, Rössner P, Boffetta P, Lindholm C, Gundy S, Lazutka J, et al. 2006. Chromosomal aberrations and SCEs as biomarkers of cancer risk. Mutat Res. 600(1-2):37–45. 10.1016/j.mrfmmm.2006.05.030 16814813
Nowacka-Zawisza M, Wiśnik E. 2017. DNA methylation and histone modifications as epigenetic regulation in prostate cancer [Review]. Oncol Rep. 38(5):2587–2596. 10.3892/or.2017.5972 29048620
Nowak-Sliwinska P, Alitalo K, Allen E, Anisimov A, Aplin AC, Auerbach R, Augustin HG, Bates DO, van Beijnum JR, Bender RHF, et al. 2018. Consensus guidelines for the use and interpretation of angiogenesis assays. Angiogenesis. 21(3):425–532. 10.1007/s10456-018-9613-x 29766399
O’Brien KM, Sandler DP, Xu Z, Kinyamu HK, Taylor JA, Weinberg CR. 2018. Vitamin D, DNA methylation, and breast cancer. Breast Cancer Res. 20(1):70. 10.1186/s13058-018-0994-y 29996894
Ohnishi K, Semi K, Yamamoto T, Shimizu M, Tanaka A, Mitsunaga K, Okita K, Osafune K, Arioka Y, Maeda T, et al. 2014. Premature termination of reprogramming in vivo leads to cancer development through altered epigenetic regulation. Cell. 156(4):663–677. 10.1016/j.cell.2014.01.005 24529372
Olsen LS, Nielsen LR, Nexø BA, Wassermann K. 1996. Somatic mutation detection in human biomonitoring. Pharmacol Toxicol. 78(6):364–373. 10.1111/j.1600-0773.1996.tb00220.x 8829195
Organisation for Economic Co-operation and Development (OECD). 2015. Test no. 478: Rodent dominant lethal test. Paris, France: OECD Publishing. 10.1787/9789264243118-en
Organisation for Economic Co-operation and Development (OECD). 2016a. Test no. 473: In vitro mammalian chromosomal aberration test. (OECD Guidelines for the Testing of Chemicals, Section 4). Paris, France: OECD Publishing. 10.1787/9789264264649-en
Organisation for Economic Co-operation and Development (OECD). 2016b. Test no. 474: Mammalian erythrocyte micronucleus test. (OECD Guidelines for the Testing of Chemicals, Section 4). Paris, France: OECD Publishing. 10.1787/9789264264762-en
Organisation for Economic Co-operation and Development (OECD). 2016c. Test no. 475: Mammalian bone marrow chromosomal aberration test. (OECD Guidelines for the Testing of Chemicals, Section 4). Paris, France: OECD Publishing. 10.1787/9789264264786-en
Organisation for Economic Co-operation and Development (OECD). 2016d. Test no. 476: In vitro mammalian cell gene mutation tests using the Hprt and xprt genes. (OECD Guidelines for the Testing of Chemicals, Section 4). Paris, France: OECD Publishing. 10.1787/9789264264809-en
Organisation for Economic Co-operation and Development (OECD). 2016e. Test no. 487: In vitro mammalian cell micronucleus test. (OECD Guidelines for the Testing of Chemicals, Section 4). Paris, France: OECD Publishing. 10.1787/9789264264861-en
Organisation for Economic Co-operation and Development (OECD). 2016f. Test no. 489: In vivo mammalian alkaline comet assay. (OECD Guidelines for the Testing of Chemicals, Section 4). Paris, France: OECD Publishing. 10.1787/9789264264885-en
Organisation for Economic Co-operation and Development (OECD). 2016g. Test no. 490: In vitro mammalian cell gene mutation tests using the thymidine kinase gene. (OECD Guidelines for the Testing of Chemicals, Section 4). Paris, France: OECD Publishing. 10.1787/9789264264908-en
Organisation for Economic Co-operation and Development (OECD). 2020. Test no. 471: Bacterial reverse mutation test. (OECD Guidelines for the Testing of Chemicals, Section 4). Paris, France: OECD Publishing. 10.1787/9789264071247-en
Organisation for Economic Co-operation and Development (OECD). 2022. Test no. 470: Mammalian erythrocyte Pig-a gene mutation assay. (OECD Guidelines for the Testing of Chemicals, Section 4). Paris, France: OECD Publishing. 10.1787/4faea90e-en
Owiti NA, Nagel ZD, Engelward BP. 2021. Fluorescence sheds light on DNA damage, DNA repair, and mutations. Trends Cancer. 7(3):240–248. 10.1016/j.trecan.2020.10.006 33203608
Pajares MJ, Alemany-Cosme E, Goñi S, Bandres E, Palanca-Ballester C, Sandoval J. 2021. Epigenetic regulation of microRNAs in cancer: Shortening the distance from bench to bedside. Int J Mol Sci. 22(14):7350. 10.3390/ijms22147350 34298969
Pang JM, Jene N, Fox SB. 2016. Assessing tumor angiogenesis in histological samples. In: Martin SG, Hewett PW, editors. Angiogenesis Protocols. 3rd ed. New York, NY: Humana Press. p. 3-33. 10.1007/978-1-4939-3628-1_1
Park HL. 2020. Epigenetic biomarkers for environmental exposures and personalized breast cancer prevention. Int J Environ Res Public Health. 17(4):1181. 10.3390/ijerph17041181 32069786
Person RJ, Tokar EJ, Xu Y, Orihuela R, Ngalame NNO, Waalkes MP. 2013. Chronic cadmium exposure in vitro induces cancer cell characteristics in human lung cells. Toxicol Appl Pharmacol. 273(2):281–288. 10.1016/j.taap.2013.06.013 23811327
Pfohl-Leszkowicz A. 2008. Chapter 7: Formation, persistence and significance of DNA adduct formation in relation to some pollutants from a broad perspective. In: Fishbein JC, editor. Advances in Molecular Toxicology: Volume 2. Amsterdam, The Netherlands: Elsevier. p. 183-239. 10.1016/s1872-0854(07)02007-3
Poirier MC. 2016. Linking DNA adduct formation and human cancer risk in chemical carcinogenesis. Environ Mol Mutagen. 57(7):499–507. 10.1002/em.22030 27346877
Poirier MC, Santella RM, Weston A. 2000. Carcinogen macromolecular adducts and their measurement. Carcinogenesis. 21(3):353–359. 10.1093/carcin/21.3.353 10688855
Ponce RA, Gelzleichter T, Haggerty HG, Heidel S, Holdren MS, Lebrec H, Mellon RD, Pallardy M. 2014. Immunomodulation and lymphoma in humans. J Immunotoxicol. 11(1):1–12. 10.3109/1547691X.2013.798388 23746314
Puar YR, Shanmugam MK, Fan L, Arfuso F, Sethi G, Tergaonkar V. 2018. Evidence for the involvement of the master transcription factor NF-κB in cancer initiation and progression. Biomedicines. 6(3):82. 10.3390/biomedicines6030082 30060453
Qian S, Golubnitschaja O, Zhan X. 2019. Chronic inflammation: Key player and biomarker-set to predict and prevent cancer development and progression based on individualized patient profiles. EPMA J. 10(4):365–381. 10.1007/s13167-019-00194-x 31832112
Schmidt R, Plath K. 2012. The roles of the reprogramming factors Oct4, Sox2 and Klf4 in resetting the somatic cell epigenome during induced pluripotent stem cell generation. Genome Biol. 13(10):251. 10.1186/gb-2012-13-10-251 23088445
Schwöbel JAH, Koleva YK, Enoch SJ, Bajot F, Hewitt M, Madden JC, Roberts DW, Schultz TW, Cronin MTD. 2011. Measurement and estimation of electrophilic reactivity for predictive toxicology. Chem Rev. 111(4):2562–2596. 10.1021/cr100098n 21401043
Seano G, Primo L. 2016. Human arterial ring angiogenesis assay. In: Martin SG, Hewett PW, editors. Angiogenesis Protocols. 3rd ed. New York, NY: Humana Press. p. 191-203. 10.1007/978-1-4939-3628-1_13
Shalini A, Tandon H, Chakraborty T. 2017. Molecular electrophilicity index – A promising descriptor for predicting toxicological property. J Bioequivalence Bioavailab. 9(6):518–527.
Sharma P, Kumar P, Sharma R. 2017. Natural killer cells - Their role in tumour immunosurveillance. J Clin Diagn Res. 11(8):BE01–BE05. 10.7860/JCDR/2017/26748.10469 28969116
Smith MT, Guyton KZ, Kleinstreuer N, Borrel A, Cardenas A, Chiu WA, Felsher DW, Gibbons CF, Goodson WH 3rd, Houck KA, et al. 2020. The key characteristics of carcinogens: Relationship to the hallmarks of cancer, relevant biomarkers, and assays to measure them. Cancer Epidemiol Biomarkers Prev. 29(10):1887–1903. 10.1158/1055-9965.EPI-19-1346 32152214
Sun Y, Miao N, Sun T. 2019. Detect accessible chromatin using ATAC-sequencing, from principle to applications. Hereditas. 156:29. 10.1186/s41065-019-0105-9 31427911
Tas F, Erturk K. 2017. Elevated erythrocyte sedimentation rate is associated with metastatic disease and worse survival in patients with cutaneous malignant melanoma. Mol Clin Oncol. 7(6):1142–1146. 10.3892/mco.2017.1440 29285390
Thompson SL, Compton DA. 2011. Chromosomes and cancer cells. Chromosome Res. 19(3):433–444. 10.1007/s10577-010-9179-y 21190130
Tokar EJ, Ancrile BB, Cunha GR, Webber MM. 2005. Stem/progenitor and intermediate cell types and the origin of human prostate cancer. Differentiation. 73(9-10):463–473. 10.1111/j.1432-0436.2005.00047.x 16351690
Tokar EJ, Diwan BA, Waalkes MP. 2010. Arsenic exposure transforms human epithelial stem/progenitor cells into a cancer stem-like phenotype. Environ Health Perspect. 118(1):108–115. 10.1289/ehp.0901059 20056578
Törnqvist M, Fred C, Haglund J, Helleberg H, Paulsson B, Rydberg P. 2002. Protein adducts: Quantitative and qualitative aspects of their formation, analysis and applications. J Chromatogr B Analyt Technol Biomed Life Sci. 778(1-2):279–308. 10.1016/S1570-0232(02)00172-1 12376136
Tozer GM, Prise VE, Cunningham VJ. 2016. Quantitative estimation of tissue blood flow rate. In: Martin SG, Hewett PW, editors. Angiogenesis Protocols. 3rd ed. New York, NY: Humana Press. p. 265-281. 10.1007/978-1-4939-3628-1_18
Trabert B, Michels KA, Anderson GL, Brinton LA, Falk RT, Geczik AM, Harris HR, Pan K, Pfeiffer RM, Qi L, et al. 2019. Circulating androgens and postmenopausal ovarian cancer risk in the Women’s Health Initiative Observational Study. Int J Cancer. 145(8):2051–2060. 10.1002/ijc.32157 30684389
Valadez-Cosmes P, Raftopoulou S, Mihalic ZN, Marsche G, Kargl J. 2022. Myeloperoxidase: Growing importance in cancer pathogenesis and potential drug target. Pharmacol Ther. 236:108052. 10.1016/j.pharmthera.2021.108052 34890688
Van Hemelrijck M, Holmberg L, Garmo H, Hammar N, Walldius G, Binda E, Lambe M, Jungner I. 2011. Association between levels of C-reactive protein and leukocytes and cancer: Three repeated measurements in the Swedish AMORIS study. Cancer Epidemiol Biomarkers Prev. 20(3):428–437. 10.1158/1055-9965.EPI-10-1190 21297038
Veglia F, Loft S, Matullo G, Peluso M, Munnia A, Perera F, Phillips DH, Tang D, Autrup H, Raaschou-Nielsen O, et al. 2008. DNA adducts and cancer risk in prospective studies: A pooled analysis and a meta-analysis. Carcinogenesis. 29(5):932–936. 10.1093/carcin/bgm286 18343884
Vryer R, Saffery R. 2017. What’s in a name? Context-dependent significance of ‘global’ methylation measures in human health and disease. Clin Epigenetics. 9:2. 10.1186/s13148-017-0311-0 28149330
Walcher L, Kistenmacher AK, Suo H, Kitte R, Dluczek S, Strauß A, Blaudszun AR, Yevsa T, Fricke S, Kossatz-Boehlert U. 2020. Cancer stem cells-origins and biomarkers: Perspectives for targeted personalized therapies. Front Immunol. 11:1280. 10.3389/fimmu.2020.01280 32849491
Ward TH, Cummings J, Dean E, Greystoke A, Hou JM, Backen A, Ranson M, Dive C. 2008. Biomarkers of apoptosis. Br J Cancer. 99(6):841–846. 10.1038/sj.bjc.6604519 19238626
Wentzensen IM, Mirabello L, Pfeiffer RM, Savage SA. 2011. The association of telomere length and cancer: A meta-analysis. Cancer Epidemiol Biomarkers Prev. 20(6):1238–1250. 10.1158/1055-9965.EPI-11-0005 21467229
Wong JYY, Bassig BA, Loftfield E, Hu W, Freedman ND, Ji BT, Elliott P, Silverman DT, Chanock SJ, Rothman N, et al. 2020. White blood cell count and risk of incident lung cancer in the UK Biobank. JNCI Cancer Spectr. 4(2):pkz102. 10.1093/jncics/pkz102 33313477
Wu HC, Kehm R, Santella RM, Brenner DJ, Terry MB. 2022. DNA repair phenotype and cancer risk: A systematic review and meta-analysis of 55 case-control studies. Sci Rep. 12(1):3405. 10.1038/s41598-022-07256-7 35233009
Xu Z, Taylor JA. 2014. Genome-wide age-related DNA methylation changes in blood and other tissues relate to histone modification, expression and cancer. Carcinogenesis. 35(2):356–364. 10.1093/carcin/bgt391 24287154
Zhang X, Zhao Q, Zhu W, Liu T, Xie SH, Zhong LX, Cai YY, Li XN, Liang M, Chen W, et al. 2017. The association of telomere length in peripheral blood cells with cancer risk: A systematic review and meta-analysis of prospective studies. Cancer Epidemiol Biomarkers Prev. 26(9):1381–1390. 10.1158/1055-9965.EPI-16-0968 28619828
Zhao Z, Shilatifard A. 2019. Epigenetic modifications of histones in cancer. Genome Biol. 20(1):245. 10.1186/s13059-019-1870-5 31747960
Zhou B, Liu J, Wang ZM, Xi T. 2012. C-reactive protein, interleukin 6 and lung cancer risk: A meta-analysis. PLoS One. 7(8):e43075. 10.1371/journal.pone.0043075 22912790
Zhou B, Shu B, Yang J, Liu J, Xi T, Xing Y. 2014. C-reactive protein, interleukin-6 and the risk of colorectal cancer: A meta-analysis. Cancer Causes Control. 25(10):1397–1405. 10.1007/s10552-014-0445-8 25053407
Zhu M, Ma Z, Zhang X, Hang D, Yin R, Feng J, Xu L, Shen H. 2022. C-reactive protein and cancer risk: A pan-cancer study of prospective cohort and Mendelian randomization analysis. BMC Med. 20(1):301. 10.1186/s12916-022-02506-x 36117174
Zippel N, Ding Y, Fleming I. 2016. A modified aortic ring assay to assess angiogenic potential in vitro. In: Martin SG, Hewett PW, editors. Angiogenesis Protocols. 3rd ed. New York, NY: Humana Press. p. 205-219. 10.1007/978-1-4939-3628-1_14