# Appendix C Systematic Review-related Tools Used by the Report on Carcinogens

The RoC program uses the following computer-based tools to gather, evaluate, and visualize data during candidate substance reviews. Not all tools are utilized for each review but may be used based on the scope and nature of the substance specific evaluation.

Table C-1 Selected Systematic Review and Other Related Tools

Tool Name | Description
Adobe Acrobat DC | Software for the creating, editing, and full text searching of PDFs.
Causaly | Online database for flexible searching to find relationship between topics.
ChemDraw | Software for drawing high quality images of chemical structures for publications.
CRAB | Fully integrated text mining tool that searches the PubMed database and identifies relevant data categories for topics including human cancer, animal tumors, and mechanistic studies.
Dexter | Semi-automated data extraction tool for abbreviated data extractions to support scoping and systematic evidence mapping products.
Distiller SR | Web-based screening tool with capabilities including AI classifiers and prioritization ranking for screening with prediction of when to stop.
DoCTER | Web-based “Document Classification and Topic Extraction Resource” software application that identifies and assigns references to topic clusters through machine learning or supervised clustering. DoCTER also helps identify the principal themes in a body of literature (Varghese et al. 2018).
HAWC | Content-management system that facilitates all aspects of environmental human health assessments. The system allows a team to store, evaluate, share, and present multiple literature searches and to record the review (e.g., quality) of the literature (Shapiro et al. 2018).
LeadScope | Computer software that links chemical and biological data, allowing researchers to visualize and interactively explore large sets of chemical compounds, their properties, and biological activities.
LION | Website that helps cancer researchers form hypotheses by providing a graph-based view of the research literature using searches from PubMed.
Lit-EmCee | Suite of tools designed to help researchers in the initial stages of literature reviews.
PubMed Abstract Sifter | Microsoft Excel based application that enhances existing search capabilities of PubMed by 1) allowing research to search effectively and triage results and 2) keep track of articles of interest. Users can operate PubMed Abstract Sifter as a stand-alone Excel program or as an integrated tab in EPA's CompTox Chemicals Dashboard.
QInsight | Online database that finds relationships between topics in various forms of data and information.
R | Open-source statistical software.
Stata | Statistical software for data science.
SWIFT Active Screener | Web-based, collaborative systematic review software application used during the document screening phase of systematic review and scoping activities (Howard et al. 2020).
SWIFT Review | Freely available interactive workbench which provides numerous tools to assist with problem formulation and literature prioritization.
Table Builder | Web-based application to store, organize data, and output data (in tabular format) for systematic review literature-based assessment. Access to Table Builder is behind the NTP firewall (Shapiro et al. 2018).
Tableau | Software to visualize and explore data. The desktop app allows users to develop visualizations, and upload of visualizations is web-based and shareable via a URL.
WebPlot Digitizer | Web-based tool to create accurate estimation of data points from plots and graphs.

## References

Howard BE, Phillips J, Tandon A, Maharana A, Elmore R, Mav D, Sedykh A, Thayer K, Merrick BA, Walker V, et al. 2020. SWIFT-Active Screener: Accelerated document screening through active learning and integrated recall estimation. Environ Int. 138:105623. 10.1016/j.envint.2020.105623 32203803
Shapiro AJ, Antoni S, Guyton KZ, Lunn RM, Loomis D, Rusyn I, Jahnke GD, Schwingl PJ, Mehta SS, Addington J, et al. 2018. Software tools to facilitate systematic review used for cancer hazard identification. Environ Health Perspect. 126(10):104501. 10.1289/EHP4224 30392397
Varghese A, Cawley M, Hong T. 2018. Supervised clustering for automated document classification and prioritization: A case study using toxicological abstracts. Environ Syst Decis. 38(3):398–414. 10.1007/s10669-017-9670-5