# Appendix B General and Exposure-specific Authoritative Sources

## B.1 Authoritative Reviews and Reports

- Agency for Toxic Substances and Disease Registry (ATSDR) Toxicological Profiles (https://www.atsdr.cdc.gov/toxprofiledocs/index.html)
- California Environmental Protection Agency Proposition 65 hazard identification documents (http://www.oehha.ca.gov/prop65/prop65_list/Newlist.html (https://nrc.uscg.mil/))
- U.S. Environmental Protection Agency (EPA) Integrated Risk Information System (IRIS) (http://cfpub.epa.gov/ncea/iris/search/index.cfm?keyword= (https://medlineplus.gov/?keyword=))
- European Chemicals Agency (ECHA) Risk Assessments (https://echa.europa.eu/ (https://www.cdc.gov/nchs/nhanes.htm))
- Health Canada Environmental Health Assessments (https://www.canada.ca/en/health-canada.html (https://www.epa.gov/air-emissions-factors-and-quantification/ap-42-compilation-air-emissions-factors))
- International Agency for Research on Cancer (IARC) Monographs (https://monographs.iarc.fr/ENG/Monographs/PDFs/index.php)
- New York State Department of Health — Health Topics A to Z (http://www.health.ny.gov/healthaz/ (https://wwwn.cdc.gov/niosh-whc/))
- National Academy of Sciences reports and publications (http://www.nationalacademies.org/publications/ (https://chemview.epa.gov/chemview))
- NTP publications, including, but not limited to, technical reports, nominations for toxicological evaluation documents, RoC, RoC background documents or monographs, and NTP Office of Health Assessment (OHAT) (formerly CERHR) monographs (http://ntp.niehs.nih.gov (http://www.fda.gov/Food/FoodScienceResearch/TotalDietStudy/ucm184293.htm); search NTP)
- World Health Organization (WHO)/United Nations Environment Programme (UNEP) International Programme on Chemical Safety (IPCS) INCHEM-related documents (http://www.inchem.org/ (https://dataweb.usitc.gov/))

## B.2 Databases or Web Resources

- Carcinogenic Potency Database (https://cebs.niehs.nih.gov/cebs/) and (https://www.lhasalimited.org/products/lhasa-carcinogenicity-database.htm (https://www.bls.gov/))
- U.S. Environmental Protection Agency (EPA) CompTox Chemical Dashboard (https://comptox.epa.gov/dashboard/)
- European Chemical Agency (ECHA) Registration, Evaluation, Authorisation, and Restriction of Chemicals (REACH) (https://www.oecd.org/chemicalsafety/risk-assessment/echemportalglobalportaltoinformationonchemicalsubstances.htm)
- European Food Safety Authority (http://www.efsa.europa.eu/en/publications.htm (https://www.cdc.gov/exposurereport/))
- International Labour Organization (http://www.ilo.org/global/publications/lang--en/index.htm (https://portal.acgih.org/s/store))
- International Uniform Chemical Information Database (http://iuclid.eu/ (https://www.cyberregs.com/cgi-exe/cpage.dll))
- National Institute for Occupational Safety and Health (NIOSH) Publications (http://www2.cdc.gov/nioshtic-2/ (https://www.efsa.europa.eu/en/publications.htm))
- U.S. NTP Integrated Chemical Environment (ICE) (https://ice.ntp.niehs.nih.gov/)
- United Nations Environment Programme (www.unep.org (http://ntp.niehs.nih.gov))
- U.S. National Library of Medicine (NLM) TOXNET
  TOXNET has moved. As part of a broader NLM reorganization, most of NLM's toxicology information services have been integrated into other NLM products and services. See https://www.nlm.nih.gov/toxnet/index.html (https://chemicalsafety.com/sds-search/) for guidance on how to access these sources.
- OECD eChem Portal (https://www.oecd.org/chemicalsafety/risk-assessment/echemportalglobalportaltoinformationonchemicalsubstances.htm)

## B.3 Exposure-specific General Sources

The initial step of the exposure section literature search strategy and evidence mapping process is to identify relevant exposure information for the candidate substance in the following sources:

- American Conference of Governmental Industrial Hygienists (ACGIH) Threshhold Limit Value/Biological Exposure Indices (TLV/BEI) documentation (available for purchase) (https://portal.acgih.org/s/store#/store/browse/cat/a0s4W00000g02f8QAA/tiles)
- ATSDR Public Health Assessment Guidance Manual (PHAGM) (https://www.atsdr.cdc.gov/pha-guidance/resources/ (https://onlinelibrary.wiley.com/doi/book/10.1002/14356007))
- ATSDR Toxicological Profiles (https://www.atsdr.cdc.gov/toxprofiledocs/index.html (https://nih.sharepoint.com/sites/NIEHS-DTT-RoC-Handbook/Shared%20Documents/General/Handbook%20appendices/www.unep.org))
- U.S. EPA AP-42, Compilation of Air Pollutant Emission Factors (https://www.epa.gov/air-emissions-factors-and-quantification/ap-42-compilation-air-emissions-factors (https://tmsearch.uspto.gov/bin/gate.exe)
  https://cfpub.epa.gov/webfire/ (https://www.nlm.nih.gov/toxnet/index.html)
  https://cfpub.epa.gov/webfire/index.cfm?action=fire.detailedSearch (https://www.cdc.gov/biomonitoring/biomonitoring_summaries.html?action=fire.detailedSearch))
- U.S. EPA Chemical Data Reporting (https://chemview.epa.gov/chemview (http://npirspublic.ceris.purdue.edu/ppis/))
- U.S. EPA CompTox Chemicals Dashboard (https://comptox.epa.gov/dashboard/)
- U.S. EPA EJView Database (https://ejscreen.epa.gov/mapper/ (https://www.health.ny.gov/healthaz/))
- U.S. EPA Enforcement and Compliance History Online (ECHO) database (https://echo.epa.gov/ (https://www.atsdr.cdc.gov/pha-guidance/resources/))
- U.S. EPA Locating and Estimating (L&E) Documents — Locating and Estimating Air Toxic Emissions from Sources of (source category or substance) (https://www.epa.gov/air-emissions-factors-and-quantification/locating-and-estimating-le-documents (https://www.uspto.gov/patents/search))
- U.S. EPA/Office of Pesticide Programs (OPP) National Pesticide Information Retrieval System (http://npirspublic.ceris.purdue.edu/ppis/ (http://www.oehha.ca.gov/prop65/prop65_list/Newlist.html))
- U.S. EPA Toxics Release Inventory (https://enviro.epa.gov/triexplorer/tri_release.chemical)
- U.S. Food and Drug Administration (FDA) Orange Book: Approved Drug Products with Therapeutic Equivalence Evaluations (http://www.fda.gov/cder/ob/default.htm (https://www.lhasalimited.org/products/lhasa-carcinogenicity-database.htm))
- U.S. FDA Pesticide Program Residue Monitoring (http://www.fda.gov/Food/FoodborneIllnessContaminants/Pesticides/UCM2006797.htm (https://www.census.gov/foreign-trade/schedules/b/index.html))
- U.S. FDA Total Diet Study http://www.fda.gov/Food/FoodScienceResearch/TotalDietStudy/ucm184293.htm (https://inchem.org/)
- Kirk-Othmer Encyclopedia of Chemical Technology (online access through the NIEHS Library)
- Material Safety Data Sheets (MSDS) (https://chemicalsafety.com/sds-search/ (http://www.fda.gov/cder/ob/default.htm))
- MedlinePlus (https://medlineplus.gov/ (http://www.fda.gov/Food/FoodborneIllnessContaminants/Pesticides/UCM2006797.htm))
- National Health and Nutrition Examination Survey (NHANES) https://www.cdc.gov/nchs/nhanes.htm (https://www.atsdr.cdc.gov/toxprofiledocs/index.html)
  https://www.cdc.gov/exposurereport/ (https://www.cdc.gov/niosh/topics/)
  https://www.cdc.gov/biomonitoring/biomonitoring_summaries.html (https://cfpub.epa.gov/ncea/iris/search/index.cfm))
- NIOSH Health Hazard Evaluations (https://www2a.cdc.gov/hhe/search.asp (http://iuclid.eu/))
- NIOSH-sponsored Research Publications and Products (https://www.cdc.gov/niosh/pubs/ (https://www.nationalacademies.org/publications/))
- NIOSH Worker Health Charts (https://wwwn.cdc.gov/niosh-whc/ (https://cfpub.epa.gov/webfire/index.cfm))
- NIOSH Workplace Safety and Health Topics (https://www.cdc.gov/niosh/topics/ (http://www.inchem.org/))
- NLM TOXNET: ChemIDplus, Hazardous Substances Data Bank (HSDB), Haz-Map, Consumer Product Information Database (formerly Household Products Database), TOXMAP (TOXNET has moved. As part of a broader NLM reorganization, most of NLM's toxicology information services have been integrated into other NLM products and services. See https://www.nlm.nih.gov/toxnet/index.html (https://www.cdc.gov/niosh/pubs/) for guidance on how to access these sources.)
- Sphera CyberRegs (https://www.cyberregs.com (https://www.epa.gov/air-emissions-factors-and-quantification/locating-and-estimating-le-documents?pg=index))
- Ullmann’s Encyclopedia of Industrial Chemistry (https://onlinelibrary.wiley.com/doi/book/10.1002/14356007 (https://www.usgs.gov/centers/national-minerals-information-center/publications))
- U.S. Air Force Defense Meteorological Satellite Program (https://catalog.data.gov/dataset/defense-meteorological-satellite-program-dmsp)
- U.S. Coast Guard National Response Center (https://nrc.uscg.mil/ (https://portal.acgih.org/s/store))
- U.S. Department of Agriculture Pesticide Recordkeeping Program (https://www.ams.usda.gov/rules-regulations/pesticide-records (https://www2.cdc.gov/nioshtic-2/))
- U.S. Department of Labor, Bureau of Labor Statistics (BLS) (https://www.bls.gov/ (https://www.ilo.org/global/publications/lang--en/index.htm))
- U.S. Geological Survey Minerals Yearbook (https://www.usgs.gov/centers/national-minerals-information-center/publications (https://www.nlm.nih.gov/toxnet/index.html)) and Commodity Sheet Summaries (https://www.usgs.gov/centers/national-minerals-information-center/mineral-commodity-summaries)
- U.S. International Trade Commission (USITC) Interactive Tariff and Trade DataWeb (import/export data) (https://dataweb.usitc.gov/ (https://ejscreen.epa.gov/mapper/)); Schedule B Codes for USITC Database Query (https://www.census.gov/foreign-trade/schedules/b/index.html (https://www.canada.ca/en/health-canada.html))
- U.S. Patent and Trademark Office Patent Search (https://www.uspto.gov/patents/search (https://cfpub.epa.gov/webfire/)); Trademark Electronic Search System (TESS) (https://tmsearch.uspto.gov/bin/gate.exe?f=tess&state=4804:91j259.1.1 (https://www2a.cdc.gov/hhe/search.asp?f=tess&state=4804:91j259.1.1))
- WHO/UNEP IPCS INCHEM-related documents (https://inchem.org/#/)