# Appendix A Glossary

## A.1 General Systematic Review Terms

bias analysis: Evaluation of internal validity that assesses probability that a specific bias is present, and if so, the direction, magnitude, and impact of bias.
Boolean operator: Words (AND, OR, NOT or AND NOT) used as conjunctions to combine or exclude keywords in a search.
Bradford Hill guidelines: A group of nine principles that can be useful in establishing evidence of a causal relationship in epidemiology. The guidelines are: strength of the association, consistency, specificity, temporality, biological gradient, plausibility, coherence, experiment, and analogy.
coherence: When the evidence across streams (e.g., human cancer, animal cancer, mechanistic) is consistent, forms a united whole, and tells a cohesive story of causality.
evidence map: An interactive visual representation of literature generated via broad literature searches to capture the state of the science and identify data gaps; also known as systematic evidence maps or systematic evidence mapping.
evidence type: Defines the model or population in which research is conducted. In systematic review, evidence stream can be in humans, animals, in vitro, or in silico.
external validity: Addresses the extent to which conclusions from one study can be generalized to other situations, e.g., relevance of experimental animal data to humans.
internal validity: Potential for bias within a study.
literature search strategy: Method and parameters needed to identify key literature.
PECO statement: (Population, Exposure, Comparison group, and Outcome): a framework used to define the type of studies included in the evaluation of human cancer studies. In animal cancer studies, Population is replaced by Model (MECO) and in mechanism studies Population is replaced by Evidence stream (EECO).
scoping review: A structured literature search to determine the extent of the body of literature on a particular topic, as well as key issues and data gaps. It also is a descriptive summary of evidence map results.
study informativeness: Ability of the study to inform the cancer hazard evaluation, also known as study utility.
study protocol: A substance specific detailed description of scoping, the conceptual frameworks, the reasoning, methods, and considerations for evaluating study informativeness, and the methods for evidence synthesis and evaluation for one or more monograph sections (e.g., human protocol, animal protocol, mechanism protocol).
study sensitivity: Ability of a study to detect a true effect.
systematic review: Standardized way of evaluating and reporting published evidence on a specific topic, or substance. A systematic review can include evidence from one or multiple evidence streams and summarizes and interprets the evidence into a refined conclusion.
triangulation: An approach to evidence synthesis that considers the overall literature base and integrated results from several different theoretical approaches, methods, and designs, which have different and unrelated sources of potential bias, to determine if findings converge on one conclusion.

## A.2 Human Exposure Terms

biomarkers: Measurable substances or characteristics in the human body that can be used to monitor the presence of a chemical in the body, biological responses, or adverse health effects.
biomonitoring: Measuring how much of a substance, its metabolites, or its biomarkers are present in the human body.
exposure models: Estimates of exposure based on combining information about environmental contaminant concentrations with information about people's activities and locations (e.g., time spent working, exercising outdoors, and sleeping; food consumption).
gray literature: Information produced outside the mainstream of published journal and monograph literature that is not controlled by commercial publishers.
NHANES: National Health and Nutrition Examination Survey (NHANES) is a program of studies (a survey designed to assess the health and nutritional status of adults and children in the United States. The survey is unique in that it combines interviews and physical examinations.
occupational exposure: Reasonably anticipated skin, eye, mucus membrane, or parenteral contact with blood or other infectious materials that may result from the performance of an employee's duties.
occurrence: Measurements of concentrations of pollutants in the environment (e.g., concentrations measured in ambient air, groundwater, etc.).
personal monitoring: Measurement of human exposure to environmental contaminants accomplished by an individual wearing a monitoring device during normal day-to-day activities.
sample matrix: A specific type of medium (e.g., surface water, drinking water) in which the analyte of interest may be contained.

## A.3 Human Cancer Terms

### A.3.1 General Human Cancer Terms

DAG: (directed acyclic graph): a tool to visually depict causal relationships in epidemiology to inform study design and statistical analysis.
meta-analysis: Statistical method combining results from multiple studies

### A.3.2 Study Population: Selection Bias

Berkson’s bias: Occurs in hospital-based case-control studies when the combination of exposure and disease under investigation increases the risk of hospital admission, leading to a systematically higher exposure rate among the hospital cases than the hospital controls (Dictionary of epidemiology, 2nd edition).
healthy volunteer: A cohort of volunteers recruited from an underlying population or subpopulation, study participants are often less likely to be from marginalized groups, as well as more likely to have higher educational or economic attainment, and/or be in better health than those in the target population; this may distort exposure-disease relationships.
healthy workers hire effect: The HWHE occurs when workers must meet minimal health criteria to begin working and are thus healthier than the general population.
healthy worker survival effect: May occur when healthier workers continue to work, and less healthy workers transfer to jobs with lower exposures, take time off, or leave work prior to the outcome. This may attenuate exposure-response relationships.
left truncation: When study subjects who are risk for the outcome do not remain observable for a later start of follow-up.
prevalent hire: When workers recruited into a cohort have a date of hire prior to the start of the study (baseline) and are still working at the start of follow-up.
selection bias: Occurs when the relationship between the exposure and outcome is different for those who participated than for the target population (those who should have been eligible for the study, including those who did not participate).

### A.3.3 Information: Exposure and Outcome

Berkson type error: Occurs when a group's average is assigned to each individual suiting the group's characteristics; will not bias effect estimates, but will make them less precise.
classical error measurement: Occurs when a quantity is measured by some device and repeated measurements vary around the true value and will bias effect estimates to the null.
detection bias: When exposure groups vary systematically in the measurement or detection of the outcome.
differential misclassification: When classification of either exposure or outcomes differs by study group.
differential recall bias: Occurs due to differences in accuracy of recall between cases and non-cases or of differential reporting of a health outcome between exposed and unexposed which can often lead to an overestimate of effect. Due to their health concerns or exposures, cases or exposed persons may have greater incentive to recall past exposures or symptoms
non-differential misclassification: When there is equal misclassification of either exposure or outcomes by study group
observer bias: A systematic difference in measured exposure or outcome due to variation in the observer.
population-based cancer registry: Registries that consolidate data from many sources and strive to provide an unbiased estimate of cancer incidence in the population.
reverse causality: Reverse causality describes the event where an association between an exposure and an outcome is not due to direct causality from exposure to outcome, but rather because the defined “outcome” actually results in a change in the defined “exposure.”

### A.3.4 Confounding

confounder: A factor that distorts the association between and exposure and outcome that is associated with both exposure (causally or non-causally) and the outcome of interest (causally) and is not an intermediate in the disease pathway.

## A.4 Animal Cancer Terms

cancer bioassay: Provides information on the possible carcinogenic effects likely to arise from repeated exposure over a considerable part of the lifespan of the species used (e.g., at least 1 year for rodents).
neoplastic (benign, malignant) end points: Tissues with non-reversible neoplastic changes.
Poly 3 test: A statistical method to determine the significance of pair-wise comparisons or overall exposure-related trends. The test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test. It takes survival differences into account by more closely approximating the total number of animal years at risk. Survival of individual animals are given a weight of one or less depending on how long they survived compared to the total study duration, raised to the power of three.
preneoplastic lesions: Tissues with reversible neoplastic changes.
subchronic toxicity study: Provides information on the possible health hazards likely to arise from repeated exposure over 28 to 90 days.
trend analysis: Analysis of trends in neoplasm incidence across at least three treatment groups (e.g., the Cochran-Armitage trend test).

## A.5 ADME Terms

absorption: Diffusion or uptake by an organism into the blood, tissue or other system.
ADME: Short for absorption, distribution, metabolism, excretion to describe the disposition of a xenobiotic substance and how it is processed by a living organism.
bioavailability: The proportion of a substance that enters the blood stream in an organism.
cytochrome P450 enzymes: Superfamily of enzymes found in the liver responsible, as well as other cells throughout the body responsible for metabolism and detoxification of xenobiotics and essential for the production of cholesterol, steroids, prostacyclin and thromboxane A_2_.
distribution: The movement or transfer of a substance from one location to another within the body.
enzyme polymorphisms: Genetic variations in metabolic enzymes which can lead to changes in the rate of metabolism of a substance, e.g., fast/slow metabolizer.
excretion: The removal of a substance or its metabolites from the body.
Good Laboratory Practices: A system which non-clinical laboratory studies are planned, performed, monitored, recorded, reported, and archived.
half-life: The time it takes for half of a radioactive isotope to decay.
metabolism: The process of changing a substance within an organism to provide energy, cell maintenance, and detoxify and eliminate xenobiotics.
parent compound: in organic chemistry, the simplest member of a class of compounds, usually a basic linear or ring structure with no added chemical groups.
PBPK: Physiologically based pharmacokinetic model based on concentrations in blood and tissue compartments.
toxicodynamics: The dynamic interactions of a substance or xenobiotic with a biological target and its biological effects.
toxicokinetics: The description of both what rate a substance or xenobiotic will enter the body and what occurs to excrete and metabolize the compound once it is in the body.
ultimate carcinogenic form; ultimate carcinogen: Chemical or metabolite that initiates a carcinogenic process.
xenobiotic: Chemical substances foreign to animal life.

## A.6 Mechanistic Terms

### A.6.1 General Mechanistic Terms

adverse outcome pathway: A structured representation of biological events leading to adverse effects, such as cancer, as is considered relevant to risk assessment.
epigenomics: The method of analyzing all modifications of DNA and associated proteins throughout the entire cell, tissue, or organism simultaneously.
epitranscriptomics: The method of analyzing all changes in RNA transcription and gene expression throughout the entire cell, tissue, or organism simultaneously under epigenetic regulation.
ex vivo: An experiment or study conducted outside a living organism from samples or tissues taking from a living organism.
genomics: The method of analyzing all of the DNA throughout an entire cell, tissue, or organism simultaneously.
in chemico: The use of abiotic chemical reactivity methods as replacements for animal/ in vivo assays.
in silico: Research or experiment conducted or produced by means of computer modeling or simulation.
in vitro: A process or study performed outside a living organism.
in vivo: A process or study that takes place in a living organism (such as in animals).
in vivo apical endpoint: An observable outcome in a whole organism, such as a clinical sign or state, that indicative of an outcome that can results from exposure to a substance.
influential literature: The key literature identified that is integral to answering the influential and level of evidence mechanistic questions.
influential questions: Questions that are substance-specific and related to the level of evidence questions and strategies; these questions are rigorously assessed in the mechanistic section of a monograph.
key event: An empirically observable step or its marker, which is a necessary element of the mode of action critical to the outcome; key events are measurable and reproducible.
mechanism/mode of action: A functional change resulting from exposure to a substance.
metabolomics: The method of analyzing all changes in metabolites throughout an entire cell, tissue, or organism simultaneously.
molecular initiating event: The initial interaction between a molecule and a biomolecule or biosystem that can be causally linked to an outcome via a pathway.
multi-omics: The method of analyzing all changes of a given set of cellular components (DNA, RNA, proteins, or metabolites) throughout an entire cell, tissue, or organism simultaneously.
omics: The method of analyzing all changes of a given cellular component (DNA, RNA, proteins, or metabolites) throughout an entire cell, tissue, or organism simultaneously.
proteomics: The method of analyzing all changes in protein expression throughout the entire cell, tissue, or organism simultaneously.
quantitative structure-activity relationship (QSAR) models: Regression or classification models used in chemical or biological sciences.
transcriptomics: The method of analyzing all changes in RNA transcription and gene expression throughout the entire cell, tissue, or organism simultaneously.

### A.6.2 Read-across Terms

analogues: A list of selected sources or group of sources and selected targets based on endpoint specific supervised similarity to be used in read-across.
analogue-based read-across: Empirical data from one or a group of analogue source chemicals can be used to predict the same endpoint for the target chemical through endpoint specific supervised similarity.
applicability domain: The response and chemical structure spaces in which the model makes predictions with a given reliability.
category-based read-across: Predicts targets starting from a group or a category of multiple sources whose physical-chemical, biological, or toxicological properties are likely to be similar or follow a regular pattern as a result of structural similarity.
data matrix: A spreadsheet or database containing the chemicals used for the prediction along with their data for selected parameters, profiles, and endpoint tree positions.
negative chemical: Chemical that has been investigated in human or animal cancer studies but have no cancer hazards (with human or animal cancer data).
read-across: A technique for predicting an endpoint (such as carcinogenicity) for a target substance by using information on this endpoint from a source substance.
source chemical: Chemical with known cancer hazards (with human or animal cancer data) used to predict the cancer hazard of the target chemical using read-across.
supervised classification: Used to predict an outcome and involve training a model using input variables (specific for the endpoint), the endpoint of interest or data-gap filling (e.g., outcome variable), and an algorithm to map the input to the output.
target chemical: Chemical with unknown cancer hazards that are predicted from sources using read-across.
uncertainty: Extent of the interpretability and defensibility of a read-across hypothesis, justification, and prediction, which are described in a transparent manner.
unsupervised clustering: Uses input data (such as general structural characteristics not specific to an endpoint) without a corresponding predicted variable or endpoint of interest.