# Foreword

The National Toxicology Program (NTP), established in 1978, is an interagency program within the Public Health Service of the Department of Health and Human Services. Its activities are executed through a partnership of the National Institute for Occupational Safety and Health of the Centers for Disease Control and Prevention, the National Center for Toxicological Research of the Food and Drug Administration, and the National Institute of Environmental Health Sciences of the National Institutes of Health where the program is administratively located. The NTP offers unique opportunity for addressing contemporary toxicological issues through research conduct, collaboration, or coordination. In partnership with others, the NTP works to develop and apply new or improved methods and approaches that will advance toxicology and better assess health effects from environmental exposures and to generate knowledge that will strengthen the science base and inform decisions by health regulatory and research agencies to safeguard the public health.

The NTP identifies environmental substances that pose a cancer risk to humans through the conduct of literature-based cancer hazard evaluations to inform their potential listing in the Report on Carcinogens (RoC), a congressionally mandated document. This handbook presents guidance for those assessments. The Report on Carcinogens and the RoC handbook are available free of charge on the NTP website (https://ntp.nieh.nih.gov/) and catalogued in PubMed, a free resource developed and maintained by the National Library of Medicine (part of the National Institutes of Health).