# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

DOI: https://doi.org/10.22427/NTP-OTHER-1008

Official citation: National Toxicology Program (NTP). 2025. NTP report on carcinogens handbook on methods for conducting cancer hazard evaluations. Research Triangle Park, NC: National Toxicology Program.