# Preface

The NTP has responsibility for preparing the congressionally mandated Report on Carcinogens (RoC). This cumulative report lists and discusses chemical, physical, and biological agents, mixtures, or exposure scenarios (collectively referred to as “substances”) that are known or reasonably anticipated to be human carcinogens. A substance profile and the listing category are provided for each listed substance, along with a concise discussion of the scientific evidence supporting the listing, information on relevant human exposures, and existing regulations and guidelines to decrease exposure to the substance.

This handbook (RoC Handbook 2025) is the guidance used for preparing literature-based cancer hazard assessments on substances under consideration for listing in the RoC. Those assessments, which are published in NTP RoC monographs, identify whether a substance is a potential cancer hazard for humans. They do not estimate the actual cancer risk to individuals associated with exposure to a substance in their daily lives, which would depend on many additional factors such as the amount and duration of exposure and each individual’s susceptibility. Importantly, identifying cancer hazards is a first step in cancer prevention.

The conduct of high-quality cancer hazard assessments on selected substances for RoC listing consideration requires the use of scientifically rigorous evaluation methods. Those methods evolve and improve over time, hence the need to update the RoC Handbook. A transparent, multi-step process is used for the review and evaluation of selected substances that applies established criteria to determine whether a substance should be listed in the RoC. As described in this updated handbook, the current four-step process includes: (1) identifying a substance to review, (2) conducting a cancer hazard assessment on the substance and applying the RoC listing criteria to the scientific evidence, (3) conducting external peer review of the draft assessment presented in an NTP RoC monograph, and (4) finalizing the assessment and publishing the monograph.

The RoC listing criteria date back to 1996 and were developed by a multi-step process with opportunities for public comment and scientific input. Recognizing the need to incorporate emerging best practices for more structured and transparent assessments, NTP developed and applied systematic review methods to the evaluation of scientific evidence from published animal and human cancer studies. These systematic methods, including guidance for identifying, selecting, and critically assessing the evidence from published cancer studies, were published in the RoC Handbook 2015.

Since release of that handbook, advances in systematic review methods and other tools have prompted the need for updated guidance. The updated guidance in this current handbook (RoC Handbook 2025) builds on those robust methods and best practices for conducting literature-based cancer hazard assessments and provides an updated suite of tools, approaches, and resources to assure scientific rigor, transparency, and confidence in the conclusions of those evaluations. The most significant updates are the development of systematic approaches for assessing the evidence from mechanistic studies followed by enhanced clarity to approaches for integrating evidence across data streams (human cancer epidemiology data, experimental animal cancer data, and cancer mechanistic data) to reach cancer hazard conclusions. Other updates to the handbook include methods to create systematic evidence maps for exploring a collection of studies, improved tools for assessing the informativeness of human cancer and experimental animal studies, greater emphasis on evaluating the impact of bias on findings from individual studies and across studies, and enhanced reporting methods to increase transparency of the assessments.

Importantly, the guidance and approaches detailed in this handbook can also serve as a resource for the scientific community. It is anticipated that this handbook will continue to be updated in the future as systematic review tools and evidence integration approaches evolve and new tools applicable to literature-based cancer hazard assessments become available.