# Peer Review

The National Toxicology Program (NTP) conducted an external peer review of the draft Handbook for Preparing Report on Carcinogens Monographs, 2nd Edition (retitled following peer review) by letter in January 2024 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft handbook.
2. Comment on the completeness of each section.

NTP carefully considered the reviewers’ comments in finalizing this report.

## Peer Reviewers

- Laura Beane-Freeman, Ph.D.
  Senior Investigator, Division of Cancer Epidemiology and Genetics
  National Cancer Institute
  Bethesda, Maryland, USA
- Lisa Bero, Ph.D.
  Professor, School of Medicine
  Chief Scientist, Center for Bioethics and Humanities
  University of Colorado CU Anschutz Medical Center
  Denver, Colorado, USA
- Terry Gordon, Ph.D.
  Professor, Department of Environmental Medicine
  New York University School of Medicine
  New York City, New York, USA
- Thomas Hartung, Ph.D.
  Professor, Department of Environmental Health and Engineering
  Johns Hopkins Bloomberg School of Public Health
  Baltimore, Maryland, USA
- David Kriebel, Ph.D.
  Director, Lowell Center for Sustainable Production
  Professor Emeritus, Department of Public Health
  University of Massachusetts Lowell
  Lowell, Massachusetts, USA
- Lisa Peterson, Ph.D.
  Professor, Division of Environmental Health Sciences
  Co-Program Leader, Masonic Cancer Center
  University of Minnesota
  Minneapolis, Minnesota, USA
- David Philips, Ph.D.
  Professor, Department of Analytical, Environmental and Forensic Sciences
  King’s College
  London, UK
- Leslie Stayner, Ph.D.
  Professor Emeritus
  University of Illinois at Chicago
  Chicago, Illinois, USA
- Emily Watkins, Ph.D.
  Senior Lecturer, Environmental and Exercise Physiology
  University of Roehampton
  London, UK