# Collaborators

- Division of Translational Toxicology, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Responsible for oversight and coordination, developing the overall framework, drafting, and critically reviewing the handbook
  Ruth M. Lunn, Dr.P.H., Project Leader
- Contributed to drafting and/or critically reviewing the handbook
  Gloria D. Jahnke, D.V.M. (Retired)
  Suril S. Mehta, Dr.P.H.
  Amy Wang, Ph.D.
- Integrated Laboratory Systems, LLC, an Inotiv Company, Research Triangle Park, North Carolina, USA
  Contributed to the coordinating activities, drafting, and critically reviewing the handbook
  Whitney D. Arroyave, Ph.D., Project Manager
- Contributed to drafting or critically reviewing the handbook
  Stanley T. Atwood, M.S. (Retired)
  William Bisson, Ph.D.
  Andrew D. Ewens, Ph.D.
  Sanford C. Garner, Ph.D. (Retired)
  M. Elizabeth Hodgson, Ph.D.
  Alton F. Peters, M.S.
  Pamela J. Schwingl, Ph.D. (Retired)
- Office of Environmental Health Hazard Assessment, California Environmental Protection Agency, Sacramento, California, USA
  Contributed to drafting and reviewing the human cancer section
  Neela Guha, Ph.D.
  M. Elizabeth Marder, Ph.D.