# Units of Measurement

Table 1 Weight/Mass

Abbreviation | Unit | Example
Da | dalton | 1 Da = 1.65 × 10^–24^ g
g | gram | 1 g = 0.3035 oz (avoirdupois)
kg | kilogram | 1 kg = 2.2 lb
Mg | megagram, metric ton | 1 Mg = 10^6^ g or 2,205 lb
μg | microgram | 1 μg = 10^–6^ g
mg | milligram | 1 mg = 1/1,000 g; 10^–3^ g
mol | mole | 1 mol = molecular weight in grams
ng | nanogram | 1 ng = 10^–9^ g
oz | ounce (avoirdupois) | 1 oz = 28.3 g
pg | picogram | 1 pg = 10^–12^ g
lb | pound | 1 lb = 0.45 kg

Table 2 Length

Abbreviation | Unit | Example
cm | centimeter | 100 cm = 1 m
dm | decimeter | 1 dm = 1/10 m
ft | foot | 1 ft = 0.3 m
in. | inch | 1 in. = 2.54 cm
km | kilometer | 1 km = 0.6 mi
m | meter | 1 m = 3.3 ft
μm | micrometer, micron | 1 μm = 10–6 m
mi | mile | 1 mi = 1.6 km
mm | millimeter | 1 mm = 1/1,000 m; 10–3 m
nm | nanometer | 1 nm = 10–9 m

Table 3 Area

Abbreviation | Unit | Example
A | acre | 1 A = 4047 m^2^
Ha | hectare | 1 Ha = 2.47 A
m^2^ | square meter | 1 m^2 =^ 10.8 ft^2^

Table 4 Volume

Abbreviation | Unit | Example
ft^3^ | cubic foot | 1 ft^3^ = 0.028 m^3^
m^3^ | cubic meter | 1 m^3^ = 35 ft^3^
cm^3^ or cc | cubic centimeter | 1 cc = approximately 1 mL
gal | gallon (U.S.) | 1 gal = 3.8 L
L | liter | 1 L = 1.05 liquid quarts
mL | milliliter | 1 mL = 10^–3^ L
p.g. | proof gallon | 1 p.g. = 1 liquid gal of spirits that contains 50% alcohol at 60°F

Table 5 Concentration

Abbreviation | Unit | Example
mM | millimolar | 1 mM = 1 M/1,000
mppcf | millions of particles per cubic foot | mppcf × 35.3 = millions of particles/m^3^
M | molar; moles of solute per liter of solution
N | normal; 1 gram equivalent of solute per liter of solution
ppm | parts per million | 1 ppm = 1 mg/kg = (mg/m^3^)(24.45)/(mol wt)
ppb | parts per billion | 1 ppb = 1 μg/kg
ppt | parts per trillion | 1 ppt = 1 ng/kg

Table 6 Pressure

Abbreviation | Unit | Example
kPa | kilopascal | 1 kPa = 0.145 lb/in^2^
MPa | megapascal | 1 MPa = 1 Pa × 10^6^
mm Hg | millimeter of mercury | 1 mm Hg = 0.0193 lb/in^2^
Pa | pascal | 1 Pa = 1 N/m^2^

Table 7 Force

Abbreviation | Unit | Example
N | newton | 1 N = 1 kg × m per s^2^

Table 8 Temperature

Abbreviation | Unit | Example
°C | degrees Celsius | = (°F – 32) × 5/9
°F | degrees Fahrenheit | = (°C × 9/5) + 32
K | kelvin | 1 K = 3.6609 x 10 ^-3^ of the thermodynamic temperature of the triple point of pure water = [(°F – 32)/1.8] + 273.15 =°C + 273.15

Table 9 Energy/Power

Abbreviation | Unit | Example
A | ampere | 1 A = 1 C/s
C | coulomb | 1 C = 1 A × s
eV | electronvolt | 1 eV = 1.6 × 10^–12^ erg
| erg | 1 erg = 10^–7^ J
J | joule | 1 J = 10^7^ erg
keV | kiloelectronvolt | 1 keV = 1,000 eV
MeV | megaelectronvolt | 1 MeV = 1 × 10^6^ eV
mW | milliwatt | 1 mW = 10^4^ erg/s

Table 10 Radiation

Abbreviation | Unit | Example
Bq | becquerel | 1 Bq = 1 disintegration per second
Ci | curie | 1 Ci = 3.7 × 10^10^ disintegrations per second
Gy | gray | 1 gy = 1 J/kg (physical quantity)
mCi | millicurie | 1 mCi = 10^–3^ Ci
pCi | picocurie | 1 pCi = 10^–12^ Ci
| rad | 1 rad = 0.01 gy
R | roentgen | 1 R = 2.58 × 10^–4^ C per kg
rem | roentgen equivalent man | 1 rem = 0.01 Sv
Sv | sievert | 1 Sv = 1 J/kg (biological effect)

Table 11 DNA or RNA (length of nucleic acid chain)

Abbreviation | Unit | Example
kb | kilobase | 1 kb = 1,000 nucleotides of RNA = 2,000 nucleotides of DNA (1,000 pairs of nucleotides)

Exponentials (Scientific Notation)

102, 103, 106, etc.: superscripts refer to the number of times 10 is multiplied by itself, e.g., 102 = 10 × 10 = 100; 103 = 10 × 10 × 10 = 1,000.