# 4,4′-Thiodianiline

CAS No. 139-65-1

Reasonably anticipated to be a human carcinogen

First listed in the Eleventh Report on Carcinogens (2004)

Figure 1

Chemical Structure of 4,4′-Thiodianiline

## Carcinogenicity

4,4′-Thiodianiline is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

### Cancer Studies in Experimental Animals

Oral exposure to 4,4′-thiodianiline caused tumors at several different tissue sites in mice and rats. Dietary administration of 4,4′-thiodianiline caused thyroid-gland cancer (follicular-cell carcinoma) in mice and rats of both sexes and liver cancer (hepatocellular carcinoma) in mice of both sexes and in male rats (NCI 1978). In rats, 4,4′-thiodianiline also caused cancer of the uterus (adenocarcinoma) in females and increased the combined incidence of benign and malignant tumors of the ear canal (Zymbal gland) in males. In addition, colon tumors in male rats and Zymbal-gland tumors in female rats were considered to be related to 4,4′-thiodianiline exposure because of the rarity of these types of tumors (Cueto and Chu 1979; NCI 1978). In studies with rasH2 transgenic mice (which carry a human gene that increases their susceptibility to cancer), dietary exposure to 4,4′-thiodianiline caused increased proliferation of thyroid follicular cells and benign thyroid-gland tumors (follicular-cell hyperplasia and adenoma) in transgenic mice and their nontransgenic littermates (Yamamoto et al. 1998a; Yamamoto et al. 1998b).

### Cancer Studies in Humans

No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to 4,4′-thiodianiline.

### Studies on Mechanisms of Carcinogenesis

4,4′-Thiodianiline caused mutations in some strains of Salmonella typhimurium (TA98 and TA100) but not others (TA1535 and TA1537). 4,4′-Thiodianiline orally administered to mice caused DNA damage in the brain, liver, urinary bladder, and lungs. In rats, 4,4′-thiodianiline binds to hemoglobin as both the diamine and the N-acetylamine. Among several bicyclic diamines studied (including 4,4′-thiodianiline), the extent of hemoglobin binding was positively correlated with carcinogenic potency (IARC 1982). Studies of the relationship between chemical structure and carcinogenic activity have suggested that the aryl-amino group of 4,4′-thiodianiline is most likely involved in its carcinogenicity. Three other dianiline compounds listed in the Report on Carcinogens as reasonably anticipated to be human carcinogens—4,4′-oxydianiline, 4,4′-methylenedianiline, and 4,4′-methylenebis(2-chloroaniline)—cause some of the same types of tumors in animals as 4,4′-thiodianiline does.

## Properties

4,4′-Thiodianiline is an aromatic amine that exists as brown powder or needles at room temperature. It is very slightly soluble in water and very soluble in alcohol, ether, and hot benzene. 4,4′-Thiodianiline is stable under normal temperatures and pressures (Akron 2009). Physical and chemical properties of 4,4′-thiodianiline are listed in Table 1.

Table 1 Properties of 4,4′-Thiodianiline

Property | Information
Molecular weight | 216.3^a^
Melting point | 108°C to 109°C^a^
Boiling point | 361°C^b^
Log K_ow_ | 2.18^b^
Water solubility | 0.310 g/L at 25°C^b^
Vapor pressure | 1.11 × 10^−5^ mm Hg at 25°C^b^

Sources: ^a^ HSDB (2009), ^b^ ChemIDplus (2009).

## Use

4,4′-Thiodianiline was used almost exclusively as a chemical intermediate in the production of three dyes: C.I. mordant yellow 16, milling red G, and milling red FR. However, only mordant yellow 16 had any commercial significance in the United States (HSDB 2009; IARC 1982); it was used to dye wool and for printing on wool, silk, and cotton (SDC 1971). Mordant yellow 16 has been used as an indicator in the U.S. government’s nerve gas detector program (SOCMA 2002). However, no uses of either 4,4′-thiodianiline or mordant yellow 16 since the early 1990s have been reported.

## Production

4,4′-Thiodianiline is prepared by reaction of aniline with sulfur (HSDB 2009; IARC 1982). U.S. production was first reported for 1941 to 1943 (IARC 1982); however, 4,4′-thiodianiline is no longer produced in the United States. The U.S. Dye Manufacturers Operating Committee of the Ecological and Toxicological Association of Dyes and Organic Pigments Manufacturers speculated in 2002 that only a few hundred pounds of 4,4′-thiodianiline were imported into the United States each year (SOCMA 2002). U.S. production of mordant yellow was last reported for 1991 (USITC 1993). Separate production statistics for mordant yellow 16 were not available; however, total mordant dye production was 33,100 kg (73,000 lb) in 1987, 29,000 kg (64,000 lb) in 1989, and 9,000 kg (19,800 lb) in 1990 (USITC 1988; 1990; 1991). In 2009, 4,4′-thiodianiline was produced in China (SRI 2009) and was available from 15 U.S. suppliers (ChemSources 2009). One U.S. producer of mordant yellow 16 was identified in 1983 and 1984 (SRI 1983; 1984), but none in 2009 (SRI 2009).

## Exposure

Dye workers may have been exposed to 4,4′-thiodianiline through skin contact, accidental ingestion, or inhalation.

## Regulations

### Department of Transportation (DOT)

Toxic dyes and toxic dye intermediates are considered hazardous materials, and special requirements have been set for marking, labeling, and transporting these materials.

### Environmental Protection Agency (EPA)

#### Emergency Planning and Community Right-to-Know Act

Toxics Release Inventory: Listed substance subject to reporting requirements.

## References

Akron. 2009. The Chemical Database. The Department of Chemistry at the University of Akron; Last accessed: 10/22/09. http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
ChemIDplus. 2009. ChemIDplus Advanced. National Library of Medicine; Last accessed: 10/22/09. http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources. 2009. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 10/22/09. http://www.chemsources.com and search on thiodianiline.
Cueto C, Chu KC. 1979. Carcinogenicity of dapsone and 4,4′-thiodianiline. In Toxicology and Occupational Medicine: Proceedings of the Tenth Inter-American Conference on Toxicology and Occupational Medicine, Key Biscayne (Miami) Florida, October 22-25, 1978, vol 4. New York, NY: Elsevier. pp. 99–108.
HSDB. 2009. Hazardous Substances Data Bank. National Library of Medicine; Last accessed: 10/22/09. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1982. 4,4′-Thiodianiline. In Some Aromatic Amines, Anthraquinones and Nitroso Compounds and Inorganic Fluorides Used in Drinking Water and Dental Preparations. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans, vol. 27. Lyon, France: International Agency for Research on Cancer. pp. 147–154.
NCI. 1978. Bioassay of 4,4′-Thiodianiline for Possible Carcinogenicity. Bethesda, MD: U.S. Department of Health and Human Services, National Institutes of Health. Technical Report Series No. 47. DHEW (NIH) Publication No. 78-847.
SDC. 1971. Colour Index, vol. 3, 3rd ed. Bradford, England: The Society of Dyers and Colourists and the American Association of Textile Chemists and Colorists. pp. 3008
SOCMA. 2002. Helmes T, Synthetic Organic Chemical Manufacturers Association, e-mail message to Jameson CW, National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, NC, 2/5/02.
SRI. 1983. Directory of Chemical Producers, United States of America. Menlo Park, CA: SRI International. pp. 939.
SRI. 1984. Directory of Chemical Producers, United States of America. Menlo Park, CA: SRI International. pp. 931.
SRI. 2009. Directory of Chemical Producers. Menlo Park, CA: SRI Consulting. Database edition; Last accessed: 10/22/09.
USITC. 1988. Synthetic Organic Chemicals, United States Production and Sales, 1987. Washington, DC: U.S. Government Printing Office. USITC Publication No 2118.
USITC. 1990. Synthetic Organic Chemicals, United States Production and Sales, 1989. Washington, DC: U.S. Government Printing Office. USITC Publication No 2338.
USITC. 1991. Synthetic Organic Chemicals, United States Production and Sales, 1990. Washington, DC: U.S. Government Printing Office. USITC Publication No 2470.
USITC. 1993. Synthetic Organic Chemicals, United States Production and Sales, 1991. Washington, DC: U.S. Government Printing Office. USITC Publication No 2607.
Yamamoto S, Urano K, Koizumi H, Wakana S, Hioki K, Mitsumori K, Kurokawa Y, Hayashi Y, Nomura T. 1998 a. Validation of transgenic mice carrying the human prototype c-Ha-ras gene as a bioassay model for rapid carcinogenicity testing. Environ Health Perspect. 106 Suppl 1:57–69. 9539005
Yamamoto S, Urano K, Nomura T. 1998 b. Validation of transgenic mice harboring the human prototype c-Ha-ras gene as a bioassay model for rapid carcinogenicity testing. Toxicol Lett. 102-103:473–478. 10.1016/S0378-4274(98)00341-5 10022298