# Thioacetamide

CAS No. 62-55-5

Reasonably anticipated to be a human carcinogen

First listed in the Third Annual Report on Carcinogens (1983)

Figure 1

Chemical Structure of Thioacetamide

## Carcinogenicity

Thioacetamide is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

### Cancer Studies in Experimental Animals

Oral exposure to thioacetamide caused tumors in two rodent species and at two different tissue sites. Dietary administration of thioacetamide caused liver cancer (hepatocellular carcinoma) in mice of both sexes and in female rats and tumors of the bile duct (cholangiocellular tumors) in rats of both sexes (IARC 1974). Since thioacetamide was listed in the Third Annual Report on Carcinogens, an additional study has been identified, which found that thioacetamide administered in the diet also caused liver cancer (hepatocellular carcinoma and papillary adenocarcinoma) in male rats (Kuroda et al. 1987).

### Cancer Studies in Humans

No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to thioacetamide

## Properties

Thioacetamide is a thioamide compound that exists at room temperature as colorless to yellow crystals with a slight odor of mercaptans (HSDB 2009; IARC 1974). It is soluble in water and ethanol, miscible with benzene and petroleum ether, and sparingly soluble in ether. It is hydrolyzed by acids or bases and reacts with salts of heavy metals. Physical and chemical properties of thioacetamide are listed in Table 1.

Table 1 Properties of Thioacetamide

Property | Information
Molecular weight | 75.1^a^
Specific gravity | 1.336 g/cm^3b^
Melting point | 113°C to 114°C^a^
Log K_ow_ | −0.26^a^
Water solubility | 163 g/L at 25°C^a^
Vapor pressure | 15.2 mm Hg at 25°C^c^
Dissociation constant (pK_a_) | 13.4^a^

Sources: ^a^HSDB (2009), ^b^Akron (2009), ^c^ChemIDplus (2009).

## Use

Thioacetamide has been used as an organic solvent in the leather, textile, and paper industries, as an accelerator in the vulcanization of buna rubber (synthetic polybutadiene), and as a stabilizer of motor fuel. However, there is no evidence that it is currently used for any of these purposes. Currently, thioacetamide is used only as a replacement for hydrogen sulfide in qualitative analyses (HSDB 2009; IARC 1974) and as a reactant in making metal salt nanoparticles (Jin et al. 2006; Liddell and Summers 2004; Liu et al. 2004; Yang et al. 2006; Zhang et al. 2002; Zhou et al. 2006).

## Production

Synthesis of thioacetamide in the United States was first reported in 1921 (IARC 1974). U.S. production in 1977 was at least 1,000 lb; however, there was no evidence of commercial production in 1982 (HSDB 2009). In 2009, thioacetamide was produced by seven manufacturers in India and one manufacturer in East Asia (SRI 2009) and was available from 45 suppliers, including 26 U.S. suppliers (ChemSources 2009). No information was found on U.S. imports or exports of thioacetamide.

## Exposure

The primary routes of potential human exposure to thioacetamide are inhalation and dermal contact (HSDB 2009). Consumers could have been exposed to thioacetamide residues through contact with products for which it was used as a solvent in the manufacturing process. According to the U.S. Environmental Protection Agency’s Toxics Release Inventory, 500 lb of thioacetamide was released to the environment in 1988. Since then, releases have not exceeded 264 lb, and no releases were reported for three years. In 2007, one facility released 10 lb of thioacetamide to an off-site hazardous-waste landfill (TRI 2009).

Occupational exposure may occur during production and use of thioacetamide (HSDB 2009). The National Occupational Hazard Survey (conducted from 1972 to 1974) estimated that 1,130 workers potentially were exposed to thioacetamide (NIOSH 1976). Clinical laboratory technicians are at greatest risk of exposure according to the National Occupational Exposure Survey (conducted from 1981 to 1983), which estimated that 786 workers, including 592 women, potentially were exposed to thioacetamide (NIOSH 1990).

## Regulations

### Environmental Protection Agency (EPA)

#### Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 10 lb.

#### Emergency Planning and Community Right-to-Know Act

Toxics Release Inventory: Listed substance subject to reporting requirements.

#### Resource Conservation and Recovery Act

Listed Hazardous Waste: Waste code for which the listing is based wholly or partly on the presence of thioacetamide = U218.

Listed as a hazardous constituent of waste.

## References

Akron. 2009. The Chemical Database. The Department of Chemistry at the University of Akron; Last accessed: 7/14/09. http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
ChemIDplus. 2009. ChemIDplus Advanced. National Library of Medicine; Last accessed: 7/14/09. http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources. 2009. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 7/14/09. http://www.chemsources.com/chemonline.html and search on CAS number.
HSDB. 2009. Hazardous Substances Data Bank. National Library of Medicine; Last accessed: 7/14/09. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1974. Thioacetamide. In Some Anti-thyroid and Related Substances, Nitrofurans and Industrial Chemicals. Lyon, France: International Agency for Research on Cancer. pp. 77–83.
Jin Y, Zhu YH, Yang XL, Jiang HB, Li CZ. 2006. In situ synthesis of sulfide-coated polystyrene composites for the fabrication of photonic crystals. J Colloid Interface Sci. 301(1):130–136. 10.1016/j.jcis.2006.04.038 16737704
Kuroda K, Terao K, Akao M. 1987. Inhibitory effect of fumaric acid on hepatocarcinogenesis by thioacetamide in rats. J Natl Cancer Inst. 79(5):1047–1051. 3479633
Liddell CM, Summers CJ. 2004. Nonspherical ZnS colloidal building blocks for three-dimensional photonic crystals. J Colloid Interface Sci. 274(1):103–106. 10.1016/j.jcis.2003.12.012 15120283
Liu Z, Liang J, Xu D, Lu J, Qian Y. 2004. A facile chemical route to semiconductor metal sulfide nanocrystal superlattices. Chem Commun (Camb). (23):2724–2725. 10.1039/b409825k 15568086
NIOSH. 1976. National Occupational Hazard Survey (1972-74). Cincinnati, OH: National Institute for Occupational Safety and Health. DHEW (NIOSH) Publication No. 78-114.
NIOSH. 1990. National Occupational Exposure Survey (1981-83). National Institute for Occupational Safety and Health; https://www.cdc.gov/noes/noes1/83086sic.html
SRI. 2009. Directory of Chemical Producers. Menlo Park, CA: SRI Consulting. Database edition; Last accessed: 7/11/09.
TRI. 2009. TRI Explorer Chemical Report. U.S. Environmental Protection Agency; Last accessed: 7/14/09. https://www.epa.gov/triexplorer/ and select Thioacetamide.
Yang L, Xing RM, Shen QM, Jiang K, Ye F, Wang JY, Ren QS. 2006. Fabrication of protein-conjugated silver sulfide nanorods in the bovine serum albumin solution. J Phys Chem B. 110(21):10534–10539. 10.1021/jp055603h 16722764
Zhang YC, Wang H, Wang B, Yan H, Yoshimura M. 2002. Low-temperature hydrothermal synthesis of pure metastable gamma-manganese sulfide (MnS) crystallites. J Cryst Growth. 243(1):214–217. 10.1016/S0022-0248(02)01495-1
Zhou G, Lu M, Xiu Z, Wang S, Zhang H, Zhou Y, Wang S. 2006. Controlled synthesis of high-quality PbS star-shaped dendrites, multipods, truncated nanocubes, and nanocubes and their shape evolution process. J Phys Chem B. 110(13):6543–6548. 10.1021/jp0549881 16570952