# Substances Listed in the Fifteenth Report on Carcinogens

Bold entries indicate new or changed listings in the Fifteenth Report on Carcinogens

## Known To Be Human Carcinogens

Aflatoxins

Alcoholic Beverage Consumption

4-Aminobiphenyl

Analgesic Mixtures Containing Phenacetin (see Phenacetin and Analgesic Mixtures Containing Phenacetin)

Aristolochic Acids

Arsenic and Inorganic Arsenic Compounds

Asbestos

Azathioprine

Benzene

Benzidine (see Benzidine and Dyes Metabolized to Benzidine)

Beryllium and Beryllium Compounds

Bis(chloromethyl) Ether and Technical-Grade Chloromethyl Methyl Ether

1,3-Butadiene

1,4-Butanediol Dimethanesulfonate

Cadmium and Cadmium Compounds

Chlorambucil

1-(2-Chloroethyl)-3-(4-methylcyclohexyl)-1-nitrosourea (see Nitrosourea Chemotherapeutic Agents)

Chromium Hexavalent Compounds

Coal Tars and Coal-Tar Pitches

Coke-Oven Emissions

Cyclophosphamide

Cyclosporin A

Diethylstilbestrol

Dyes Metabolized to Benzidine (Benzidine Dye Class) (see Benzidine and Dyes Metabolized to Benzidine)

Epstein-Barr Virus (see Viruses: Eight Listings)

Erionite

Estrogens, Steroidal

Ethylene Oxide

Formaldehyde

Helicobacter pylori (Chronic Infection)

Hepatitis B Virus (see Viruses: Eight Listings)

Hepatitis C Virus (see Viruses: Eight Listings)

Human Immunodeficiency Virus Type 1 (see Viruses: Eight Listings)

Human Papillomaviruses: Some Genital-Mucosal Types (see Viruses: Eight Listings)

Human T-Cell Lymphotrophic Virus Type 1 (see Viruses: Eight Listings)

Kaposi Sarcoma–Associated Herpesvirus (see Viruses: Eight Listings)

Melphalan

Merkel Cell Polyomavirus (see Viruses: Eight Listings)

Methoxsalen with Ultraviolet A Therapy

Mineral Oils: Untreated and Mildly Treated

Mustard Gas

2-Naphthylamine

Neutrons (see Ionizing Radiation)

Nickel Compounds (see Nickel Compounds and Metallic Nickel)

Radon (see Ionizing Radiation)

Silica, Crystalline (Respirable Size)

Solar Radiation (see Ultraviolet Radiation Related Exposures)

Soots

Strong Inorganic Acid Mists Containing Sulfuric Acid

Sunlamps or Sunbeds, Exposure to (see Ultraviolet Radiation Related Exposures)

Tamoxifen

2,3,7,8-Tetrachlorodibenzo-p-dioxin

Thiotepa

Thorium Dioxide (see Ionizing Radiation)

Tobacco Smoke, Environmental (see Tobacco-Related Exposures)

Tobacco Smoking (see Tobacco-Related Exposures)

Tobacco, Smokeless (see Tobacco-Related Exposures)

o-Toluidine

Trichloroethylene

Ultraviolet Radiation, Broad-Spectrum (see Ultraviolet Radiation Related Exposures)

Vinyl Chloride (see Vinyl Halides [selected])

Wood Dust

X-Radiation and Gamma Radiation (see Ionizing Radiation)

## Reasonably Anticipated To Be Human Carcinogens

Acetaldehyde

2-Acetylaminofluorene

Acrylamide

Acrylonitrile

Adriamycin

2-Aminoanthraquinone

o-Aminoazotoluene

1-Amino-2,4-dibromoanthraquinone

2-Amino-3,4-dimethylimidazo[4,5-f]quinoline (see Heterocyclic Amines [Selected])

2-Amino-3,8-dimethylimidazo[4,5-f]quinoxaline (see Heterocyclic Amines [Selected])

1-Amino-2-methylanthraquinone

2-Amino-3-methylimidazo[4,5-f]quinoline (see Heterocyclic Amines [Selected])

2-Amino-1-methyl-6-phenylimidazo[4,5-b]pyridine (see Heterocyclic Amines [Selected])

Amitrole

o-Anisidine and Its Hydrochloride

Antimony Trioxide

Azacitidine

Basic Red 9 Monohydrochloride

Benz[a]anthracene (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

Benzo[b]fluoranthene (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

Benzo[j]fluoranthene (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

Benzo[k]fluoranthene (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

Benzo[a]pyrene (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

Benzotrichloride

2,2-Bis(bromomethyl)-1,3-propanediol (Technical Grade)

Bis(chloroethyl) Nitrosourea (see Nitrosourea Chemotherapeutic Agents)

Bromochloroacetic Acid (see Haloacetic Acids Found as Water Disinfection By-Products [Selected])

Bromodichloroacetic Acid (see Haloacetic Acids Found as Water Disinfection By-Products [Selected])

Bromodichloromethane

1-Bromopropane

Butylated Hydroxyanisole

Captafol

Carbon Tetrachloride

Ceramic Fibers (Respirable Size)

Chloramphenicol

Chlorendic Acid

Chlorinated Paraffins (C_12_, 60% Chlorine)

Chlorodibromoacetic Acid (see Haloacetic Acids Found as Water Disinfection By-Products [Selected])

1-(2-Chloroethyl)-3-cyclohexyl-1-nitrosourea (see Nitrosourea Chemotherapeutic Agents)

Chloroform

3-Chloro-2-methylpropene

4-Chloro-o-phenylenediamine

Chloroprene

p-Chloro-o-toluidine and Its Hydrochloride

Chlorozotocin (see Nitrosourea Chemotherapeutic Agents)

Cisplatin

Cobalt and Cobalt Compounds That Release Cobalt Ions In Vivo (see Cobalt-Related Exposures)

Cobalt–Tungsten Carbide: Powders and Hard Metals (see Cobalt-Related Exposures)

p-Cresidine

Cumene

Cupferron

Dacarbazine

Danthron

2,4-Diaminoanisole Sulfate

2,4-Diaminotoluene

Diazoaminobenzene

Dibenz[a,h]acridine (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

Dibenz[a,j]acridine (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

Dibenz[a,h]anthracene (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

7H-Dibenzo[c,g]carbazole (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

Dibenzo[a,e]pyrene (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

Dibenzo[a,h]pyrene (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

Dibenzo[a,i]pyrene (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

Dibenzo[a,l]pyrene (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

Dibromoacetic Acid (see Haloacetic Acids Found as Water Disinfection By-Products [Selected])

1,2-Dibromo-3-chloropropane

1,2-Dibromoethane

2,3-Dibromo-1-propanol

Dichloroacetic Acid (see Haloacetic Acids Found as Water Disinfection By-Products [Selected])

1,4-Dichlorobenzene

3,3′-Dichlorobenzidine and Its Dihydrochloride

Dichlorodiphenyltrichloroethane

1,2-Dichloroethane

Dichloromethane

1,3-Dichloropropene (Technical Grade)

Diepoxybutane

Diesel Exhaust Particulates

Di(2-ethylhexyl) Phthalate

Diethyl Sulfate

Diglycidyl Resorcinol Ether

3,3′-Dimethoxybenzidine (see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine)

4-Dimethylaminoazobenzene

3,3′-Dimethylbenzidine (see 3,3′-Dimethylbenzidine and Dyes Metabolized to 3,3′-Dimethylbenzidine)

Dimethylcarbamoyl Chloride

1,1-Dimethylhydrazine

Dimethyl Sulfate

Dimethylvinyl Chloride

1,6-Dinitropyrene (see Nitroarenes [Selected])

1,8-Dinitropyrene (see Nitroarenes [Selected])

1,4-Dioxane

Disperse Blue 1

Dyes Metabolized to 3,3′-Dimethoxybenzidine (3,3′-Dimethoxybenzidine Dye Class) (see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine)

Dyes Metabolized to 3,3′-Dimethylbenzidine (3,3′-Dimethylbenzidine Dye Class) (see 3,3′-Dimethylbenzidine and Dyes Metabolized to 3,3′-Dimethylbenzidine)

Epichlorohydrin

Ethylene Thiourea

Ethyl Methanesulfonate

Furan

Glass Wool Fibers (Inhalable), Certain

Glycidol

Hexachlorobenzene

Hexachloroethane

Hexamethylphosphoramide

Hydrazine and Hydrazine Sulfate

Hydrazobenzene

Indeno[1,2,3-cd]pyrene (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

Iron Dextran Complex

Isoprene

Kepone

Lead and Lead Compounds

Lindane, Hexachlorocyclohexane (Technical Grade), and Other Hexachlorocyclohexane Isomers

2-Methylaziridine

5-Methylchrysene (see Polycyclic Aromatic Hydrocarbons: 15 Listings)

4,4′-Methylenebis(2-chloroaniline)

4,4′-Methylenebis(N,N-dimethyl)benzenamine

4,4′-Methylenedianiline and Its Dihydrochloride

Methyleugenol

Methyl Methanesulfonate

N-Methyl-N′-Nitro-N-Nitrosoguanidine (see N-Nitrosamines: 15 Listings)

Metronidazole

Michler’s Ketone

Mirex

Naphthalene

Nickel, Metallic (see Nickel Compounds and Metallic Nickel)

Nitrilotriacetic Acid

o-Nitroanisole

Nitrobenzene

6-Nitrochrysene (see Nitroarenes [Selected])

Nitrofen

Nitrogen Mustard Hydrochloride

Nitromethane

2-Nitropropane

1-Nitropyrene (see Nitroarenes [Selected])

4-Nitropyrene (see Nitroarenes [Selected])

N-Nitrosodi-n-butylamine (see N-Nitrosamines: 15 Listings)

N-Nitrosodiethanolamine (see N-Nitrosamines: 15 Listings)

N-Nitrosodiethylamine (see N-Nitrosamines: 15 Listings)

N-Nitrosodimethylamine (see N-Nitrosamines: 15 Listings)

N-Nitrosodi-n-propylamine (see N-Nitrosamines: 15 Listings)

N-Nitroso-N-ethylurea (see N-Nitrosamines: 15 Listings)

4-(N-Nitrosomethylamino)-1-(3-pyridyl)-1-butanone (see N-Nitrosamines: 15 Listings)

N-Nitroso-N-methylurea (see N-Nitrosamines: 15 Listings)

N-Nitrosomethylvinylamine (see N-Nitrosamines: 15 Listings)

N-Nitrosomorpholine (see N-Nitrosamines: 15 Listings)

N-Nitrosonornicotine (see N-Nitrosamines: 15 Listings)

N-Nitrosopiperidine (see N-Nitrosamines: 15 Listings)

N-Nitrosopyrrolidine (see N-Nitrosamines: 15 Listings)

N-Nitrososarcosine (see N-Nitrosamines: 15 Listings)

o-Nitrotoluene

Norethisterone

Ochratoxin A

4,4′-Oxydianiline

Oxymetholone

Pentachlorophenol and By-products of Its Synthesis

Phenacetin (see Phenacetin and Analgesic Mixtures Containing Phenacetin)

Phenazopyridine Hydrochloride

Phenolphthalein

Phenoxybenzamine Hydrochloride

Phenytoin and Phenytoin Sodium

Polybrominated Biphenyls

Polychlorinated Biphenyls

Procarbazine and Its Hydrochloride

Progesterone

1,3-Propane Sultone

β-Propiolactone

Propylene Oxide

Propylthiouracil

Reserpine

Riddelliine

Safrole

Selenium Sulfide

Streptozotocin (see Nitrosourea Chemotherapeutic Agents)

Styrene

Styrene-7,8-oxide

Sulfallate

Tetrachloroethylene

Tetrafluoroethylene

Tetranitromethane

Thioacetamide

4,4′-Thiodianiline

Thiourea

Toluene Diisocyanates

Toxaphene

Tribromoacetic Acid (see Haloacetic Acids Found as Water Disinfection By-Products [Selected])

2,4,6-Trichlorophenol

1,2,3-Trichloropropane

Tris(2,3-dibromopropyl) Phosphate

Ultraviolet Radiation A (see Ultraviolet Radiation Related Exposures)

Ultraviolet Radiation B (see Ultraviolet Radiation Related Exposures)

Ultraviolet Radiation C (see Ultraviolet Radiation Related Exposures)

Urethane

Vinyl Bromide (see Vinyl Halides [Selected])

4-Vinyl-1-cyclohexene Diepoxide

Vinyl Fluoride (see Vinyl Halides [Selected])