# Safrole

CAS No. 94-59-7

Reasonably anticipated to be a human carcinogen

First listed in the Second Annual Report on Carcinogens (1981)

Also known as 5-(2-propenyl)-1,3-benzodioxole

Figure 1

Chemical Structure of Safrole

## Carcinogenicity

Safrole is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

### Cancer Studies in Experimental Animals

Safrole caused liver tumors in two rodent species and by two different routes of exposure. Dietary administration of safrole caused liver cancer (hepatocellular carcinoma) in male mice and benign or malignant liver tumors (hepatocellular carcinoma or adenoma or cholangiocarcinoma) in rats of both sexes (IARC 1972; 1976). Liver cancer (hepatocellular carcinoma) was also observed in mice of both sexes administered safrole by stomach tube from 7 to 28 days of age, followed by dietary exposure for up to 82 weeks, and in infant male mice administered safrole by subcutaneous injection.

Since safrole was listed in the Second Annual Report on Carcinogens, an additional study in mice has been identified. The incidence of liver tumors (adenoma and carcinoma) was increased in male mice exposed during infancy via milk and in adult female mice administered safrole in the diet (Vesselinovitch 1983).

### Cancer Studies in Humans

No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to safrole.

## Properties

Safrole, a naturally occurring substance, is a derivative of the aromatic phenol ether 1,3-benzodioxole (HSDB 2009). It exists at room temperature as a colorless or pale-yellow oil with an odor of sassafras. It is practically insoluble in water, insoluble in glycerine, slightly soluble in propylene glycol, soluble in alcohol, and miscible with chloroform and ether. Physical and chemical properties of safrole are listed in Table 1.

Table 1 Properties of Safrole

Property | Information
Molecular weight | 162.2^a^
Density | 1.1 g/cm^3^ at 20°C^a^
Melting point | 11.2°C^a^
Boiling point | 234.5°C^a^
Log K_ow_ | 3.45^b^
Water solubility | 0.121 g/L at 25°C^b^
Vapor pressure | 0.0618 mm Hg at 25°C^b^

Sources: ^a^HSDB (2009), ^b^ChemIDplus (2009).

## Use

Safrole has been used as a flavoring agent in drugs and in the manufacture of heliotropin, perfumes, soaps, and piperonyl butoxide (a compound used in a variety of insecticides to enhance the pesticidal properties of other active ingredients) (HSDB 2009; IARC 1972; 1976). Safrole has also been used as a preservative in mucilage and library paste and as a flotation frother. Oil of sassafras, which contains safrole, was formerly used to flavor some soft drinks, such as root beer. However, this use or any other addition of safrole or oil of sassafras to food was banned in the United States in 1960 (HSDB 2009; IARC 1972; 1976). Safrole has also been used in the illicit production of the drug 3,4-methylenedioxymethamphetamine (MDMA, or ecstasy), and the U.S. Drug Enforcement Administration has designated safrole a List I Chemical (DEA 2009; 2010).

## Production

Safrole is produced by distillation of oils rich in safrole (IARC 1976). U.S. production of safrole was 257,000 lb in 1969 and 277,000 lb in 1970, but had fallen to 12,000 lb by 1977 (HSDB 2009; IARC 1976). In 2009, safrole was available from 11 U.S. suppliers (ChemSources 2009). The U.S. Environmental Protection Agency (EPA) reported that U.S. production plus imports of safrole totaled 10,000 to 500,000 lb in 1998 (EPA 2004) and less than 500,000 lb in 2006 (EPA 2009); no other reports on production of safrole were found. U.S. imports of safrole from 1980 to 2005 ranged from 11,000 to 132,000 lb (HSDB 2009; USITC 2009), but no imports were reported for 2017 (USITC 2018). U.S. exports of safrole in 2017 were about 30,000 lb (USITC 2018), similar to exports of about 35,000 lb in 1998 (USITC 2009).

## Exposure

The potential routes of exposure to safrole are inhalation, ingestion, and dermal contact (HSDB 2009). Safrole may be ingested in edible spices, including sassafras, cinnamon, nutmeg, mace, star anise, ginger, black and white pepper, and from chewing betel quid; all of these substances contain naturally occurring safrole at low levels (Archer and Jones 2002; HSDB 2009; IARC 1976). Safrole is also present in herbal products derived from the sassafras tree, including the creole herb gumbo filé (Carlson and Thompson 1997). The concentration of safrole can be reduced during the cooking process (Farag and Abo-Zeid 1997). Based on common ingestion patterns, the estimated daily intake of safrole is 0.3 mg (Rietjens et al. 2005). Safrole was also identified as a minor constituent of bidi cigarettes (mean concentration = 33 μg per cigarette) (Stanfill et al. 2006) and regular tobacco cigarettes (median concentration = 5.2 ng/g of tobacco) (Stanfill and Ashley 1999). Safrole may also be a contaminant of MDMA, of which safrole is a major ingredient (Świst et al. 2005).

According to EPA’s Toxics Release Inventory, relatively small amounts of safrole have been released to the environment since 1988, mostly as air emissions, except in 1999 and 2001, when a large amount of safrole was released to on-site hazardous-waste landfills or off-site non-hazardous-waste landfills. In 2007, two facilities released a total of 1,000 lb of safrole, each facility releasing roughly half the total (TRI 2009); one facility released the waste to air, and the other to an off-site landfill.

Occupational exposure to safrole may occur by inhalation or dermal contact (HSDB 2009). Health professionals, such as pharmacists, physicians, and nurses, could be exposed during formulation, preparation, administration, or clean-up of drugs containing safrole or sassafras. The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that 6,475 workers, including 5,761 women, potentially were exposed to safrole (NIOSH 1990).

## Regulations

### Drug Enforcement Administration (Dept. of Justice)

Safrole is listed as a Class I chemical, and manufacturers, distributors, importers and exporters are subject to record-keeping, reporting, and other requirements, as prescribed in 21 CFR 1309, 1310, and 1313.

### Environmental Protection Agency (EPA)

#### Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 100 lb.

#### Emergency Planning and Community Right-to-Know Act

Toxics Release Inventory: Listed substance subject to reporting requirements.

#### Resource Conservation and Recovery Act

Listed Hazardous Waste: Waste code for which the listing is based wholly or partly on the presence of safrole = U203.

Listed as a hazardous constituent of waste.

### Food and Drug Administration (FDA, an HHS agency)

Safrole is prohibited from direct addition to food or use as human food.

## References

Archer VE, Jones DW. 2002. Capsaicin pepper, cancer and ethnicity. Med Hypotheses. 59(4):450–457. 10.1016/S0306-9877(02)00152-4 12208187
Carlson M, Thompson RD. 1997. Liquid chromatographic determination of safrole in sassafras-derived herbal products. J AOAC Int. 80(5):1023–1028. 10.1093/jaoac/80.5.1023 9325580
ChemIDplus. 2009. ChemIDplus Advanced. National Library of Medicine; Last accessed: 9/9/09. http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry number and search on CAS number.
ChemSources. 2009. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 9/9/09. http://www.chemsources.com/chemonline.html and search on safrole.
DEA. 2009. Safrole and sassafras oil are used in the illicit manufacture of MDMA. Drug Enforcement Administration; http://www.deadiversion.usdoj.gov/chem_prog/advisories/safrole.htm
DEA. 2010. Section 1310.02 Substances Covered. Drug Enforcement Administration; Last accessed: 10/9/10. http://www.deadiversion.usdoj.gov/21cfr/cfr/1310/1310_02.htm
EPA. 2004. Non-confidential IUR Production Volume Information. U.S. Environmental Protection Agency; https://www.epa.gov/oppt/iur/tools/data/2002-vol.html and search on CAS number
EPA. 2009. Non-confidential 2006 IUR Records by Chemical, Including Manufacturing, Processing and Use Information. U.S. Environmental Protection Agency; https://cfpub.epa.gov/iursearch/2006_iur_natlcheminfo.cfm?id=6628
Farag SE, Abo-Zeid M. 1997. Degradation of the natural mutagenic compound safrole in spices by cooking and irradiation. Nahrung. 41(6):359–361. 10.1002/food.19970410609 9467788
HSDB. 2009. Hazardous Substances Data Bank. National Library of Medicine; Last accessed: 7/14/09. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1972. Safrole, isosafrole, and dihydroisosafrole. In Some Inorganic Substances, Chlorinated Hydrocarbons, Aromatic Amines, N-Nitroso Compounds and Natural Products. Lyon, France: International Agency for Research on Cancer. pp. 169–174.
IARC. 1976. Safrole, isosafrole, and dihydrosafrole. In Some Naturally Occurring Substances. Lyon, France: International Agency for Research on Cancer. pp. 231–244.
NIOSH. 1990. National Occupational Exposure Survey (1981-83). National Institute for Occupational Safety and Health; https://www.cdc.gov/noes/noes1/83472sic.html
Rietjens IM, Martena MJ, Boersma MG, Spiegelenberg W, Alink GM. 2005. Molecular mechanisms of toxicity of important food-borne phytotoxins. Mol Nutr Food Res. 49(2):131–158. 10.1002/mnfr.200400078 15635687
Stanfill SB, Ashley DL. 1999. Solid phase microextraction of alkenylbenzenes and other flavor-related compounds from tobacco for analysis by selected ion monitoring gas chromatography-mass spectrometry. J Chromatogr A. 858(1):79–89. 10.1016/S0021-9673(99)00796-7 10544893
Stanfill SB, Brown CR, Yan XJ, Watson CH, Ashley DL. 2006. Quantification of flavor-related compounds in the unburned contents of bidi and clove cigarettes. J Agric Food Chem. 54(22):8580–8588. 10.1021/jf060733o 17061837
Świst M, Wilamowski J, Parczewski A. 2005. Basic and neutral route specific impurities in MDMA prepared by different synthesis methods. Comparison of impurity profiles. Forensic Sci Int. 155(2-3):100–111. 10.1016/j.forsciint.2004.11.003 16226147
TRI. 2009. TRI Explorer Chemical Report. U.S. Environmental Protection Agency; Last accessed: 9/9/09. https://www.epa.gov/triexplorer/ and select Safrole
USITC. 2009. USITC Interactive Tariff and Trade DataWeb. United States International Trade Commission; https://dataweb.usitc.gov/scripts/user_set.asp and search on HTS no. 2932940000.
USITC. 2018. USITC Interactive Tariff and Trade DataWeb. United States International Trade Commission; https://dataweb.usitc.gov/scripts/user_set.asp and search on HTS no. 2932940000.
Vesselinovitch SD. 1983. Perinatal hepatocarcinogenesis. Biol Res Pregnancy Perinatol. 4(1):22–25. 6303459