# Furan

CAS No. 110-00-9

Reasonably anticipated to be a human carcinogen

First listed in the Eighth Report on Carcinogens (1998)

Figure 1

Chemical Structure of Furan

## Carcinogenicity

Furan is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

### Cancer Studies in Experimental Animals

Oral exposure to furan caused tumors at several different tissue sites in mice and rats. Administration of furan by stomach tube for up to two years caused benign and/or malignant liver tumors (hepatocellular adenoma or carcinoma) in mice and rats of both sexes. It also caused bile-duct cancer (cholangiocarcinoma) and mononuclear-cell leukemia in rats of both sexes and benign adrenal-gland tumors (pheochromocytoma) in mice of both sexes (NTP 1993). Similar administration of furan to male rats for 9 to 13 weeks caused bile-duct cancer (cholangiocarcinoma) by 16 months after the end of exposure (Elmore and Sirica 1993; Maronpot et al. 1991). Since furan was listed in the Eighth Report on Carcinogens, an additional study in mice has been identified. Intraperitoneal injection of furan caused benign or malignant liver tumors (hepatocellular adenoma or carcinoma) in newborn male mice (Johansson et al. 1997).

### Cancer Studies in Humans

No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to furan.

### Studies on Mechanisms of Carcinogenesis

In bacteria, furan caused gene mutations in Salmonella typhimurium strain TA100 (Lee et al. 1994) and in Escherichia coli containing bacteriophage T7 (Rontó et al. 1992), but not in S. typhimurium strains TA98 (Lee et al. 1994), TA1535, or TA1537 (Mortelmans et al. 1986). It did not cause gene mutations in Drosophila melanogaster (Foureman et al. 1994). In mammalian in vitro systems, it caused gene mutations in mouse lymphoma cells (McGregor et al. 1988), DNA damage in Chinese hamster ovary (CHO) cells (NTP 1993), and chromosomal damage in CHO cells with mammalian metabolic activation (IARC 1995; NTP 1993), but it did not cause DNA damage in mouse or rat hepatocytes (NTP 1993; Wilson et al. 1992). In mammalian in vivo systems, furan caused chromosomal aberrations in bone marrow of mice (Johansson et al. 1997; NTP 1993), but did not cause DNA damage in mouse bone marrow or hepatocytes or rat hepatocytes (NTP 1993; Wilson et al. 1992).

A current hypothesis for the mechanism of furan-induced carcinogenesis is metabolic activation of furan by cytochrome P450 to a reactive and cytotoxic intermediate that stimulates cell replication, increasing the likelihood of tumor induction (Chen et al. 1995; Kedderis et al. 1993). The postulated reactive metabolite is cis-2-butene-1,4-dial, which was characterized as a furan metabolite by Chen et al. (1995). This reactive metabolite probably explains furan’s binding reactivity with proteins both in vitro (in uninduced and induced male rat liver microsomes) and in vivo (with male rat liver protein) (Burka et al. 1991; Parmar and Burka 1993). Furan metabolites may react with DNA, but no radiotracer was detected in DNA from livers of rats administered [^14^C]furan (Burka et al. 1991).

## Properties

Furan is a cyclic dienic ether that is a clear, colorless liquid with an ethereal odor (Akron 2009; HSDB 2009). It can turn brown upon standing (HSDB 2009). Furan is slightly soluble in water and is soluble at greater than 10% in acetone, benzene, ether, and ethanol. It is extremely flammable and may form explosive peroxides in the absence of inhibitors (Akron 2009). Physical and chemical properties of furan are listed in Table 1.

Table 1 Properties of Furan

Property | Information
Molecular weight | 68.1^a^
Specific gravity | 0.9371 at 19.4°C/4°C^a^
Melting point | −85.6°C^a^
Boiling point | 31.4°C at 760 mm Hg^a^
Log K_ow_ | 1.34^a^
Water solubility | 10 g/L at 25°C^b^
Vapor pressure | 600 mm Hg at 25°C^b^
Vapor density relative to air | 2.3^a^

Sources: ^a^HSDB (2009), ^b^ChemIDplus (2009).

## Use

Furan is used primarily as an intermediate in the synthesis and production of tetrahydrofuran, pyrrole, and thiophene. Hydrogenation of furan over a nickel catalyst produces high yields of tetrahydrofuran and is a source of commercial tetrahydrofuran (IARC 1995; NTP 1993). Furan is also used in the formation of lacquers, as a solvent for resins, and in the production of agricultural chemicals, stabilizers, and pharmaceuticals (HSDB 2009; IARC 1995).

## Production

Commercial production of furan involves decarbonylation of furfural over a palladium-charcoal catalyst. The commercial product is at least 99% pure (IARC 1995). U.S. production of furan was between 10 and 50 million pounds from 1986 to 1998 (EPA 2004), but combined production and imports had fallen to between 1 million and 10 million pounds by 2014 (EPA 2016). In 1986, U.S. imports of furan resins totaled about 9.7 million pounds (HSDB 2009). No information on U.S. imports and exports of furan was found. In 2009, furan was available from 20 suppliers worldwide, including 11 U.S. suppliers (ChemSources 2009).

## Exposure

Evidence that the U.S. general population is exposed to furan comes from findings of furan in human blood and exhaled breath. The 2013–2014 National Health and Nutrition Examination Survey (NHANES) found that the 95th-percentile concentration of furan in whole blood was 0.091 ng/mL, based on a sample of 3,203 individuals of all ages, both genders, and all race and ethnicity groups (CDC 2018a). People are exposed to furan primarily through ingestion of food, inhalation of contaminated air, and tobacco smoking. The pattern of commercial use suggests that minimal exposure to the general population would be expected through contact with products contaminated with furan (NTP 1993). However, furan can be formed in foods during processing.

Furan was measured by the U.S. Food and Drug Administration in various foods and beverages, including infant formulas, baby foods, soups and sauces, fruits and vegetables, bread, and meat products. The maximum concentration found was 125 ppb (μg/kg) in canned soup (FDA 2005). A second study confirmed that heat-treated foods, such as canned and jarred foods, contained measurable quantities of furan (up to 240 μg/kg in canned chili) (Becalski et al. 2005). Furan was measured in fruit juice at concentrations near 1 μg/kg (Goldmann et al. 2005). In several brands of brewed coffee, the highest furan concentration found was 84.2 ppb (FDA 2005; Ho et al. 2005). Furan was also identified as a component of coffee aroma that has antioxidant activity (Fuster et al. 2000). Furan was also detected at a concentration of 110 μg/kg in jarred baby food containing cooked vegetables (Goldmann et al. 2005). However, furan concentrations decreased after the jar was opened and the contents were heated. When food is heated in a container, furan concentrations increase if the container remains closed, but not if it is open (Hasnip et al. 2006). Furan does not appear to be transferred from the packaging or gasket of the can or jar. Furan is formed from ascorbic acid, fructose, sucrose, and glucose when foods are heated or irradiated (Fan 2005). Furan production increases greatly with decreasing pH of the medium; 1,600 times as much furan is formed at pH 3 as is formed at pH 8.

Furan is found at higher levels in the blood and exhaled breath of smokers than in the general population. The 2013–2014 NHANES found that in a sample of 951 cigarette smokers of all ages and both genders, the 95th-percentile concentration in whole blood was 0.172 ng/mL (CDC 2018b). In one study in Texas, furan was detected in the exhaled breath of two of three male smokers and four of five male nonsmokers (HSDB 2009). Smokers exhaled between 0.25 and 98 μg of furan per hour, and nonsmokers exhaled between 0.33 and 28 μg/h. In a study in Chicago, 15 of 387 breath samples collected from 54 male and female nonsmokers had detectable levels of furan, with a mean concentration of 0.55 ng/L. Furan was also detected in the indoor air of homes in the Chicago, Illinois, and Washington, D.C., metropolitan areas (NTP 1999). Furan also occurs naturally in pine rosin and in volatile emissions from sorb trees (HSDB 2009).

The primary route of occupational exposure to furan is inhalation. The industrial processes in which furan is used are conducted in closed systems, and its volatility requires that furan be handled in closed containers; therefore, occupational exposure is limited (NTP 1993). The National Occupational Hazard Survey (conducted from 1972 to 1974) estimated that 244 workers potentially were exposed to furan (NIOSH 1976). The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that 35 workers (mostly in the Business Services industry), including 7 women, potentially were exposed to furan (NIOSH 1990).

## Regulations

### Department of Transportation (DOT)

Furan is considered a hazardous material, and special requirements have been set for marking, labeling, and transporting this material.

### Environmental Protection Agency (EPA)

#### Clean Air Act

Listed as a mobile source air toxic.

Prevention of Accidental Release: Threshold quantity (TQ) = 5,000 lb.

#### Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 100 lb.

#### Emergency Planning and Community Right-to-Know Act

Toxics Release Inventory: Listed substance subject to reporting requirements.

Reportable quantity (RQ) = 100 lb.

Threshold planning quantity (TPQ) = 500 lb.

#### Resource Conservation and Recovery Act

Listed Hazardous Waste: Waste code for which the listing is based wholly or partly on the presence of furan = U124.

### Occupational Safety and Health Administration (OSHA, Dept. of Labor)

Considered a highly hazardous chemical; threshold quantity (TQ) = 500 lb.

## Guidelines

### National Institute for Occupational Safety and Health (NIOSH, CDC, HHS)

Immediately dangerous to life and health (IDLH) limit = 13 ppm (35.1 mg/m^3^).

## References

Akron. 2009. The Chemical Database. Akron, OH: The Department of Chemistry at the University of Akron; http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
Becalski A, Forsyth D, Casey V, Lau BP, Pepper K, Seaman S. 2005. Development and validation of a headspace method for determination of furan in food. Food Addit Contam. 22(6):535–540. 10.1080/02652030500129170 16019826
Burka LT, Washburn KD, Irwin RD. 1991. Disposition of [^14^C]furan in the male F344 rat. J Toxicol Environ Health. 34(2):245–257. 10.1080/15287399109531564 1920528
CDC. 2018 a. Fourth National Report on Human Exposure to Environmental Chemicals, Updated Tables, March 2018. Vol. 1. Atlanta, GA: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention; Furan; p. 674–675.
CDC. 2018 b. Fourth National Report on Human Exposure to Environmental Chemicals, Updated Tables, March 2018. Vol. 2. Atlanta, GA: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention; Furan; p. 658.
ChemIDplus. 2009. ChemIDplus Advanced. Bethesda, MD: National Library of Medicine; http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources. 2009. Chem Sources - Chemical Search. Pendleton, SC: Chemical Sources International; http://www.chemsources.com/chemonline.html and search on furan.
Chen LJ, Hecht SS, Peterson LA. 1995. Identification of cis-2-butene-1,4-dial as a microsomal metabolite of furan. Chem Res Toxicol. 8(7):903–906. 10.1021/tx00049a001 8555403
Elmore LW, Sirica AE. 1993. “Intestinal-type” of adenocarcinoma preferentially induced in right/caudate liver lobes of rats treated with furan. Cancer Res. 53(2):254–259. 7678071
EPA. 2004. Non-confidential IUR Production Volume Information. Washington, DC: U.S. Environmental Protection Agency. https://www.epa.gov/oppt/iur/tools/data/2002-vol.html and search on CAS number.
EPA. 2016. Chemical Data Reporting Summary: Furan. Washington, DC: U.S. Environmental Protection Agency. https://chemview.epa.gov/chemview and search on CAS number or substance name and select Manufacturing, Processing, Use, and Release Data Maintained by EPA and select Chemical Data Reporting Details.
Fan X. 2005. Formation of furan from carbohydrates and ascorbic acid following exposure to ionizing radiation and thermal processing. J Agric Food Chem. 53(20):7826–7831. 10.1021/jf051135x 16190637
FDA. 2005. Exploratory Data on Furan in Food: Individual Food Products. Silver Spring, MD: U.S. Food and Drug Administration. https://www.fda.gov/Food/FoodSafety/FoodContaminantsAdulteration/ChemicalContaminants/Furan/UCM078439
Foureman P, Mason JM, Valencia R, Zimmering S. 1994. Chemical mutagenesis testing in Drosophila. IX. Results of 50 coded compounds tested for the National Toxicology Program. Environ Mol Mutagen. 23(1):51–63. 10.1002/em.2850230109 8125083
Fuster MD, Mitchell AE, Ochi H, Shibamoto T. 2000. Antioxidative activities of heterocyclic compounds formed in brewed coffee. J Agric Food Chem. 48(11):5600–5603. 10.1021/jf000605e 11087525
Goldmann T, Perisset A, Scanlan F, Stadler RH. 2005. Rapid determination of furan in heated foodstuffs by isotope dilution solid phase micro-extraction-gas chromatography—mass spectrometry (SPME-GC-MS). Analyst (Lond). 130(6):878–883. 10.1039/b419270b 15912236
Hasnip S, Crews C, Castle L. 2006. Some factors affecting the formation of furan in heated foods. Food Addit Contam. 23(3):219–227. 10.1080/02652030500539766 16517523
Ho IP, Yoo SJ, Tefera S. 2005. Determination of furan levels in coffee using automated solid-phase microextraction and gas chromatography/mass spectrometry. J AOAC Int. 88(2):574–576. 15859085
HSDB. 2009. Hazardous Substances Data Bank. Bethesda, MD: National Library of Medicine; http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1995. Dry Cleaning, Some Chlorinated Solvents and Other Industrial Chemicals. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans. Vol. 63. Lyon, France: International Agency for Research on Cancer; Furan; p. 393–407.
Johansson E, Reynolds S, Anderson M, Maronpot R. 1997. Frequency of Ha-ras-1 gene mutations inversely correlated with furan dose in mouse liver tumors. Mol Carcinog 18(4):199-205. <199:AID-MC3>3.0.CO;2-910.1006/taap.1993.1246 9142214
Kedderis GL, Carfagna MA, Held SD, Batra R, Murphy JE, Gargas ML. 1993. Kinetic analysis of furan biotransformation by F-344 rats in vivo and in vitro. Toxicol Appl Pharmacol. 123(2):274–282. 10.1006/taap.1993.1246 8248934
Lee H, Bian SS, Chen YL. 1994. Genotoxicity of 1,3-dithiane and 1,4-dithiane in the CHO/SCE assay and the Salmonella/microsomal test. Mutat Res. 321(4):213–218. 10.1016/0165-1218(94)90072-8 7515159
Maronpot RR, Giles HD, Dykes DJ, Irwin RD. 1991. Furan-induced hepatic cholangiocarcinomas in Fischer 344 rats. Toxicol Pathol. 19(4 Pt. 2):561–570. 10.1177/019262339101900401 1668599
McGregor DB, Brown A, Cattanach P, Edwards I, McBride D, Riach C, Caspary WJ. 1988. Responses of the L5178Y tk+/tk- mouse lymphoma cell forward mutation assay: III. 72 coded chemicals. Environ Mol Mutagen. 12(1):85–154. 10.1002/em.2860120111 3383842
Mortelmans K, Haworth S, Lawlor T, Speck W, Tainer B, Zeiger E. 1986. Salmonella mutagenicity tests: II. Results from the testing of 270 chemicals. Environ Mutagen. 8 Suppl. 7:1–119. 10.1002/em.2860080802 3516675
NIOSH. 1976. National Occupational Hazard Survey (1972-74). Cincinnati, OH: National Institute for Occupational Safety and Health. DHEW (NIOSH) Publication No. 78-114.
NIOSH. 1990. National Occupational Exposure Survey (1981-83). Cincinnati, OH: National Institute for Occupational Safety and Health. https://www.cdc.gov/noes/noes1/34185sic.html
NTP. 1993. Toxicology and Carcinogenesis Studies of Furan (CAS No. 110-00-9) in F344 Rats and B6C3F1 Mice (Gavage Studies). Research Triangle Park, NC: National Toxicology Program. Technical Report Series no. 402.
NTP. 1999. NTP Report on Carcinogens Background Document for Furan. Research Triangle Park, NC: Integrated Laboratory Systems.
Parmar D, Burka LT. 1993. Studies on the interaction of furan with hepatic cytochrome P-450. J Biochem Toxicol. 8(1):1–9. 10.1002/jbt.2570080103 8492299
Rontó G, Gróf P, Buisson JP, Einhorn J, Demerseman P. 1992. Genotoxic effectivity: Comparison of 36 nitrated furan and arenofuran derivatives on a quantitative scale. Statistical comparison of T7 and other short-term tests. Mutagenesis. 7(4):243–249. 10.1093/mutage/7.4.243 1518407
Wilson DM, Goldsworthy TL, Popp JA, Butterworth BE. 1992. Evaluation of genotoxicity, pathological lesions, and cell proliferation in livers of rats and mice treated with furan. Environ Mol Mutagen. 19(3):209–222. 10.1002/em.2850190305 1572344