# Dichlorodiphenyltrichloroethane

CAS No. 50-29-3

Reasonably anticipated to be a human carcinogen

First listed in the Fourth Annual Report on Carcinogens (1985)

Also known as DDT or 1,1,1-trichloro-2,2-bis(p-chlorophenyl)-ethane

Figure 1

Chemical Structure of Dichlorodiphenyltrichloroethane

## Carcinogenicity

Dichlorodiphenyltrichloroethane (DDT) is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

### Cancer Studies in Experimental Animals

DDT caused liver tumors in two rodent species and by two different routes of exposure. It caused primarily malignant primary liver-cell tumors (hepatocellular carcinoma) in mice of both sexes and in rats (of unspecified sex) following dietary exposure; in mice of both sexes following administration by stomach tube; and in female mice following subcutaneous injection reviewed by IARC (1991). Increased incidences of lung tumors and malignant lymphoma following oral exposure to DDT were observed in some, but not all, of the studies in mice.

### Cancer Studies in Humans

No epidemiological studies of the carcinogenicity of DDT in humans were identified at the time DDT was listed in the Fourth Annual Report on Carcinogens. Since then, a number of epidemiological studies of human cancer and DDT exposure have been identified. Studies reviewed in 1991 by the International Agency for Research on Cancer were inconclusive because of co-exposure to numerous pesticides and the small sizes of the study groups (IARC 1991).

Epidemiological studies conducted since 1991 have mainly been case-control or nested case-control studies, plus a few prospective or occupational cohort studies, and include over 20 studies of breast cancer. Comparison of the results of breast-cancer studies has been complicated by differences in exposure assessment, dietary factors, breast-tumor type and estrogen-receptor status, age, menopausal status, lactation history, body mass status, race or ethnicity, or exposure to other potential carcinogens (Calle et al. 2002; Clapp et al. 2008; Eskenazi et al. 2009; Snedeker 2001). The majority of breast-cancer studies (mostly of older women in the United States) did not find statistically significant associations with estimated exposure or with serum or adipose-tissue levels of DDT or 1,1-dichloro-2,2-bis(p-chlorophenyl)ethylene (DDE, a metabolite of DDT). See the reviews above and ATSDR (2002); ATSDR (2008); Lopez-Cervantes et al. (2004). However, positive associations between DDT exposure and breast cancer were reported in a few studies among women with higher levels of exposure and among certain subgroups of women (Cohn et al. 2007; Høyer et al. 2000; Romieu et al. 2000; Rubin et al. 2006; Wolff et al. 1993).

Several studies have investigated the association between DDT or DDE exposure and cancer at other tissue sites. One study reported an association between DDT exposure and leukemia among agricultural workers (Morris-Brown et al. 1990). Increased risk or incidence of multiple myeloma with DDT exposure was found in a case-control study of farmers (Eriksson and Karlsson 1992) and a cohort proportionate-mortality study of pesticide applicators who had used 94% DDT (Cocco et al. 1997). Increased risk of liver cancer also has been associated with serum DDT level (McGlynn et al. 2006), DDT pesticide application (Cocco et al. 1997), and levels of DDE in adipose tissue (Cocco et al. 2000). Increased risks of cancer at other tissue sites, such as the gallbladder (Shukla et al. 2001), prostate (Settimi et al. 2003), and testes (McGlynn et al. 2008), have been reported in one study for each site.

## Properties

DDT is a chlorinated aromatic hydrocarbon insecticide (NCI 1978) that in its pure form exists at room temperature as colorless to off-white needles or powder with a slight aromatic odor (Akron 2009; HSDB 2009). It is practically insoluble in water, but it is soluble in many organic solvents, including acetone, benzene, benzyl benzoate, carbon tetrachloride, chlorobenzene, cyclohexanone, ethanol, ethyl ether, gasoline, isopropanol, kerosene, morpholine, peanut oil, pine oil, tetralin, and tributyl phosphate (HSDB 2009; IARC 1974). DDT is highly soluble in lipids (HSDB 2009). It is very stable and exceptionally persistent in the environment (IPCS 1989). Technical-grade DDT is a mixture of three forms, p,p′-DDT (85%), o,p′-DDT (15%), and o,o′-DDT (trace amounts) (ATSDR 2002). Technical-grade DDT may also contain DDE and 1,1-dichloro-2,2-bis(p-chlorophenyl)ethane (DDD) as contaminants; both are breakdown products of DDT. Physical and chemical properties of DDT are listed in Table 1.

Table 1 Properties of Dichlorodiphenyltrichloroethane

Property | Information
Molecular weight | 354.5
Specific gravity | 0.98 to 0.99
Melting point | 108.5°C
Boiling point | 260°C
Log K_ow_ | 6.91
Water solubility | 5.50 × 10^−6^ g/L at 25°C
Vapor pressure | 1.6 × 10^−7^ mm Hg at 20°C

Source: HSDB (2009).

## Use

DDT was first used in the United States as an insecticide in 1939 (ATSDR 2002). From 1946 to 1972, DDT was one of the most widely used insecticides in the world (HSDB 2009). It was used for the control of insect pests such as the pink bollworm on cotton, codling moth on deciduous fruits, Colorado potato beetle, and European corn borer (ATSDR 2002). In the public health field, DDT was used to control malaria, typhus, and other insect-transmitted diseases and to treat body lice (HSDB 2009). It was also used for mothproofing clothing (ATSDR 2002). Its usage peaked in the 1960s, but in 1972, it was banned for the vast majority of uses in the United States (ATSDR 2002; HSDB 2009). DDT is currently used in the United States only under Public Health Service supervision for public health emergencies and by the U.S. Department of Agriculture or U.S. military for health quarantine. It is also still used in many countries where malaria is endemic, as an insecticide to control mosquitoes (HSDB 2009).

## Production

Technical DDT was first synthesized in 1874, and commercial production in the United States had begun by 1945 (ATSDR 2002; HSDB 2009). In 1962, 180.4 million pounds of DDT was produced in the United States for use on 334 agricultural commodities. In 1971, production in the United States was estimated at 4.4 million pounds. After 1972, when DDT was banned for most uses in the United States, it was produced only for export, and by 2002, it was no longer produced in the United States (ATSDR 2002). In 1972, the last year when DDT was imported into the United States, imports totaled 441,000 lb (ATSDR 2002; HSDB 2009). In 1978, the last year for which U.S. exports were reported specifically for DDT, they totaled 30.2 million pounds (HSDB 2009).

## Exposure

Despite the 1972 U.S. ban of DDT, human exposure continues because of its extensive former use, its current use in some areas of the world, and the persistence of DDT and its breakdown products in the environment (ATSDR 2002). DDT has been measured in numerous human tissues in the U.S. population and in other populations around the world. The 2009–2010 National Health and Nutrition Examination Survey (CDC 2018) detected p,p′-DDT in the serum of blood samples from the U.S. general population. The arithmetic-mean lipid-adjusted levels differed by sex, age, and race or ethnicity group. They were higher (1) in women than in men, (2) in adults (aged 20 or older) than in adolescents (aged 12 to 19), (3) in older adults (aged 40 or older) than in younger adults, and (4) in non-white people (Hispanic or black) than in white people. Levels in white adults ranged from 2.51 to 4.86 ng/g of lipid. The highest levels were found in older Hispanic women, regardless of race (75.2 ng/g for women aged 40 to 59 and 37.0 ng/g for women over 59), especially Mexican-American women (113 ng/g for women aged 40 to 59 and 56.9 ng/g for women over 59).

DDT accumulates in fatty tissues and is usually found in higher concentrations in human milk than in cow’s milk or other infant foods. In the United States, mean concentrations of DDT were 0.99 mg/kg (990 ng/g) in milk fat from Arkansas women in 1986, 28.8 ppb (ng/g) in serum from consumers of Great Lakes fish in 1982, and 252 ng/g in adipose tissue from a national sample of individuals age 45 years or older in 1986 (ATSDR 2002). The median concentration of DDT in plasma samples from 407 highly exposed Inuit individuals living in Greenland was 35 μg/kg of lipid (35 ng/g) of (Bjerregaard et al. 2001). DDT was detected in 95% of the samples from this population.

Exposure to DDT occurs because it is still released into the atmosphere through spraying in some areas of the world. In addition, it volatilizes from soil in areas where it was formerly used. The volatilization and deposition cycle may be repeated many times, resulting in widespread distribution of DDT worldwide. In addition, DDT readily accumulates in animal fat and thus bioaccumulates through the food chain. DDT and its breakdown products have been found throughout the world, from the Arctic to the Antarctic, having been detected in ambient and indoor air, precipitation (rain and snow), water, soil, and animal and plant tissues. The residual levels of DDT in the environment have declined and continue to decline, but because of DDT’s high persistence, it will be present at low levels for decades. Currently, human exposure to DDT and its breakdown products is primarily through dietary ingestion, particularly of meat, fish, poultry, and root and leafy vegetables. The highest dietary exposure occurs among indigenous Arctic populations that eat traditional foods such as seal, whale, or caribou. The highest average daily intake was observed in the eastern Arctic, where total daily intake of DDT and all of its metabolites was 24.2 to 27.8 μg/day. The foods contributing the most were beluga whale blubber (316 μg/g of wet weight) and narwhal whale blubber (273 μg/g) (ATSDR 2002).

## Regulations

### Department of Transportation (DOT)

DDT is considered a hazardous substance and a marine pollutant, and special requirements have been set for marking, labeling, and transporting this material, including transporting it in tank cars.

### Environmental Protection Agency (EPA)

#### Clean Water Act

Designated a hazardous substance.

Effluent Guidelines: Listed as a toxic pollutant.

Water Quality Criteria: Based on fish or shellfish and water consumption = 0.000030 μg/L; based on fish or shellfish consumption only = 0.000030 μg/L.

#### Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 1 lb.

#### Federal Insecticide, Fungicide, and Rodenticide Act

Registrations for nearly all uses of DDT have been cancelled.

#### Resource Conservation and Recovery Act

Listed Hazardous Waste: Waste code for which the listing is based wholly or partly on the presence of DDT = U061.

Listed as a hazardous constituent of waste.

### Food and Drug Administration (FDA, an HHS agency)

Action levels for DDT in various food items and in processed animal feed range from 0.05 to 5 ppm.

### Occupational Safety and Health Administration (OSHA, Dept. of Labor)

While this section accurately identifies OSHA’s legally enforceable PELs for this substance in 2018, specific PELs may not reflect the more current studies and may not adequately protect workers.

Permissible exposure limit (PEL) = 1 mg/m^3^.

Potential for dermal absorption.

## Guidelines

### American Conference of Governmental Industrial Hygienists (ACGIH)

Threshold limit value – time-weighted average (TLV-TWA) = 1 mg/m^3^.

### National Institute for Occupational Safety and Health (NIOSH, CDC, HHS)

Immediately dangerous to life and health (IDLH) limit = 500 mg/m^3^.

Recommended exposure limit (time-weighted-average workday) = 0.5 mg/m^3^.

Listed as a potential occupational carcinogen.

## References

Akron. 2009. The Chemical Database. Akron, OH: The Department of Chemistry at the University of Akron; http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
ATSDR. 2002. Toxicological Profile for DDT, DDD, and DDE. Atlanta, GA: Agency for Toxic Substances and Disease Registry. https://www.atsdr.cdc.gov/toxprofiles/tp35.pdf
ATSDR. 2008. Addendum to the DDT/DDD/DDE Toxicological Profile. Atlanta, GA: Agency for Toxic Substances and Disease Registry. https://www.atsdr.cdc.gov/toxprofiles/ddt_addendum.pdf
Bjerregaard P, Dewailly E, Ayotte P, Pars T, Ferron L, Mulvad G. 2001. Exposure of Inuit in Greenland to organochlorines through the marine diet. J Toxicol Environ Health A 62(2):69-81. 10.1080/009841001455490 10.1080/009841001455490
Calle EE, Frumkin H, Henley SJ, Savitz DA, Thun MJ. 2002. Organochlorines and breast cancer risk. CA Cancer J Clin 52(5):301-309. 10.3322/canjclin.52.5.301 10.3322/canjclin.52.5.301
CDC. 2018. p,p'-Dichlorodiphenyltrichloroethane (DDT). In Fourth National Report on Human Exposure to Environmental Chemicals, Updated Tables, March 2018. vol 2. Atlanta, GA: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention. pp. 27-34.
Clapp RW, Jacobs MM, Loechler EL. 2008. Environmental and occupational causes of cancer: New evidence 2005-2007. Rev Environ Health 23(1):1-37. 10.1515/REVEH.2008.23.1.1 10.1515/REVEH.2008.23.1.1
Cocco P, Blair A, Congia P, Saba G, Ecca AR, Palmas C. 1997. Long-term health effects of the occupational exposure to DDT. A preliminary report. Ann N Y Acad Sci 837:246-256. 10.1111/j.1749-6632.1997.tb56878.x 10.1111/j.1749-6632.1997.tb56878.x
Cocco P, Kazerouni N, Zahm SH. 2000. Cancer mortality and environmental exposure to DDE in the United States. Environ Health Perspect 108(1):1-4. 10.1289/ehp.001081 10.1289/ehp.001081
Cohn BA, Wolff MS, Cirillo PM, Sholtz RI. 2007. DDT and breast cancer in young women: new data on the significance of age at exposure. Environ Health Perspect 115(10):1406-1414. 10.1289/ehp.10260 10.1289/ehp.10260
Eriksson M, Karlsson M. 1992. Occupational and other environmental factors and multiple myeloma: a population based case-control study. Br J Ind Med 49(2):95-103. 10.1136/oem.49.2.95 10.1136/oem.49.2.95
Eskenazi B, Chevrier J, Rosas LG, Anderson HA, Bornman MS, Bouwman H, Chen A, Cohn BA, de Jager C, Henshel DS, et al. 2009. The Pine River statement: Human health consequences of DDT use. Environ Health Perspect 117(9):1359-1367. 10.1289/ehp.11748 10.1289/ehp.11748
Høyer AP, Jorgensen T, Grandjean P, Hartvig HB. 2000. Repeated measurements of organochlorine exposure and breast cancer risk (Denmark). Cancer Causes Control 11(2):177-184. 10.1023/A:1008926219539 10.1023/A:1008926219539
HSDB. 2009. Hazardous Substances Data Bank. Bethesda, MD: National Library of Medicine; http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1974. Some Organochlorine Pesticides. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans. Vol. 5. Lyon, France: International Agency for Research on Cancer; DDT and associated substances; p. 83–124.
IARC. 1991. Occupational Exposures in Insecticide Application, and Some Pesticides. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans. Vol. 53. Lyon, France: International Agency for Research on Cancer; DDT and associated compounds; p. 179–249.
IPCS. 1989. Environmental Health Criteria No. 83. DDT and Its Derivatives. Geneva, Switzerland: International Programme on Chemical Safety. http://www.inchem.org/documents/ehc/ehc/ehc89.htm
Lopez-Cervantes M, Torres-Sanchez L, Tobias A, Lopez-Carrillo L. 2004. Dichlorodiphenyldichloroethane burden and breast cancer risk: A meta-analysis of the epidemiologic evidence. Environ Health Perspect. 112(2):207–214. 10.1289/ehp.112-1241830 14754575
McGlynn KA, Abnet CC, Zhang M, Sun XD, Fan JH, O’Brien TR, Wei WQ, Ortiz-Conde BA, Dawsey SM, Weber JP, et al. 2006. Serum concentrations of 1,1,1-trichloro-2,2-bis(p-chlorophenyl)ethane (DDT) and 1,1-dichloro-2,2-bis(p-chlorophenyl)ethylene (DDE) and risk of primary liver cancer. J Natl Cancer Inst 98(14):1005-1010. 10.1093/jnci/djj266 10.1093/jnci/djj266
McGlynn KA, Quraishi SM, Graubard BI, Weber JP, Rubertone MV, Erickson RL. 2008. Persistent organochlorine pesticides and risk of testicular germ cell tumors. J Natl Cancer Inst 100(9):663-671. 10.1093/jnci/djn101 10.1093/jnci/djn101
Morris-Brown LM, Blair A, Gibson R, Everett GD, Cantor KP, Schuman LM, Burmeister LF, Van Lier SF, Dick F. 1990. Pesticide exposures and other agricultural risk factors for leukemia among men in Iowa and Minnesota. Cancer Res. 50(20):6585–6591. 2208120
NCI. 1978. Bioassay of DDT, TDE, and p,p'-DDE for Possible Carcinogenicity (CAS Nos. 50-29-3, 72-54-8, 72-55-9). Bethesda, MD: National Institutes of Health. Technical Report Series No. 131, DHEW (NIH) Publication No. 78-1386.
Romieu I, Hernandez-Avila M, Lazcano-Ponce E, Weber JP, Dewailly E. 2000. Breast cancer, lactation history, and serum organochlorines. Am J Epidemiol. 152(4):363–370. 10.1093/aje/152.4.363 10968381
Rubin CH, Lanier A, Kieszak S, Brock JW, Koller KR, Strosnider H, Needham L, Zahm S, Harpster A. 2006. Breast cancer among Alaska Native women potentially exposed to environmental organochlorine chemicals. Int J Circumpolar Health. 65(1):18–27. 10.3402/ijch.v65i1.17885 16544644
Settimi L, Masina A, Andrion A, Axelson O. 2003. Prostate cancer and exposure to pesticides in agricultural settings. Int J Cancer. 104(4):458–461. 10.1002/ijc.10955 12584743
Shukla VK, Rastogi AN, Adukia TK, Raizada RB, Reddy DC, Singh S. 2001. Organochlorine pesticides in carcinoma of the gallbladder: A case-control study. Eur J Cancer Prev. 10(2):153–156. 10.1097/00008469-200104000-00006 11330456
Snedeker SM. 2001. Pesticides and breast cancer risk: A review of DDT, DDE, and dieldrin. Environ Health Perspect. 109 Suppl 1:35–47. 11250804
Wolff MS, Toniolo PG, Lee EW, Rivera M, Dubin N. 1993. Blood levels of organochlorine residues and risk of breast cancer. J Natl Cancer Inst. 85(8):648–652. 10.1093/jnci/85.8.648 8468722