# Diazoaminobenzene

CAS No. 136-35-6

Reasonably anticipated to be a human carcinogen

First listed in the Eleventh Report on Carcinogens (2004)

Also known as 1,3-diphenyltriazene

Figure 1

Chemical Structure of Diazoaminobenzene

## Carcinogenicity

Diazoaminobenzene is reasonably anticipated to be a human carcinogen based on (1) evidence from studies in experimental animals and with human tissue demonstrating that diazoaminobenzene is metabolized to benzene, a known human carcinogen, and (2) evidence that diazoaminobenzene causes genetic damage. Studies in rats and mice have shown that the metabolism of diazoaminobenzene to benzene is quantitative. Benzene was listed in the First Annual Report on Carcinogens in 1980 based on human epidemiological studies demonstrating that exposure to benzene causes leukemia. Benzene also causes cancer at numerous tissue sites in rodents.

### Studies on Mechanisms of Carcinogenesis

Diazoaminobenzene is metabolized to benzene and to the known rodent carcinogen aniline; it also shares similar genotoxic and toxicological properties with these two carcinogens (Bordelon et al. 2005). In studies on the absorption, distribution, metabolism, and excretion of diazoaminobenzene orally administered to rats and mice, benzene and aniline were detected in blood, benzene was detected in exhaled breath, and metabolites of benzene and aniline were excreted in urine. Exhalation of benzene implies systemic exposure to this metabolite (Mathews and De Costa 1999; NTP 2002). Metabolites of diazoaminobenzene in the blood of rats and the urine of rats and mice included hydroquinone, muconic acid, and phenylmercapturic acid, which share benzene oxide as a common intermediate, demonstrating that the metabolic pathway of diazoaminobenzene is similar to that of benzene. In studies with human liver slices, diazoaminobenzene was reduced to benzene and aniline (Mathews and De Costa 1999). The proposed metabolic pathway for diazoaminobenzene is reductive cleavage by liver enzymes or by bacteria in the digestive tract to form benzene, aniline, and nitrogen. Benzene and aniline then are metabolized by cytochrome P450 and conjugating enzymes. Electron spin resonance studies have shown that in rats, phenyl radicals also are produced as intermediates in metabolism of diazoaminobenzene to benzene (Kadiiska et al. 2000).

In 16-day toxicity studies of rats and mice exposed to diazoaminobenzene (dermally, but without protection of the application site, to allow oral exposure through grooming), the symptoms observed were similar to those characteristic of benzene or aniline toxicity. Diazoaminobenzene also appeared to induce toxic effects not observed with aniline or benzene, including skin lesions at the application site (NTP 2002).

Diazoaminobenzene caused mutations in bacteria with mammalian microsomal metabolic activation (Zeiger et al. 1987). It also caused chromosomal aberrations in plants and micronucleus formation in the bone marrow of rodents (Ress et al. 2002). Benzene and aniline do not cause mutations in bacteria, but they do induce micronucleus formation in rodents. However, diazoaminobenzene orally administered to mice induced more micronuclei than did equimolar doses of benzene or a mixture of benzene and aniline. The greater genotoxicity of diazoaminobenzene than of its metabolites benzene and aniline may be due to the effects of phenyl radicals formed during its metabolism.

### Cancer Studies in Experimental Animals

No studies were identified that evaluated whether exposure to diazoaminobenzene caused cancer in experimental animals.

### Cancer Studies in Humans

No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to diazoaminobenzene.

## Properties

Diazoaminobenzene is an aromatic amine that exists as small golden-yellow crystals at room temperature. It is insoluble in water but freely soluble in benzene, ether, and hot alcohol. It is stable under normal temperatures and pressures (Akron 2009). Physical and chemical properties of diazoaminobenzene are listed in Table 1.

Table 1 Properties of Diazoaminobenzene

Property | Information
Molecular weight | 197.1^a^
Melting point | 98°C^a^
Boiling point | 305°C^b^
Log K_ow_ | 3.99^c^
Water solubility | 0.500 g/L^c^
Vapor pressure | 1.91 × 10^−5^ mm Hg at 25°C^c^
Vapor density relative to air | 6.8^b^
Dissociation constant (pK_b_) | 13.00^b^

Sources: ^a^ HSDB (2009), ^b^ Akron (2009), ^c^ ChemIDplus (2009).

## Use

Diazoaminobenzene is used as a chemical intermediate, complexing agent, and polymer additive (Mathews and De Costa 1999). It has uses associated with organic synthesis and dye and insecticide manufacture (Lewis 1997), and it is an effective dopant for laser ablation (micro-machining) of polymethylmethacrylate (Bolle et al. 1990). Diazoaminobenzene has been identified as a low-level contaminant in the dyes D&C red no. 33, FD&C yellow no. 5 (tartrazine), and FD&C yellow no. 6; all three are permitted for use in drugs and cosmetics, and the latter two are permitted in food (FDA 2010).

## Production

Diazoaminobenzene is produced by reaction of aniline with isoamyl nitrate (Smith and Ho 1990) or by diazotization of aniline dissolved in hydrochloric acid with sodium nitrite, followed by addition of sodium acetate (HSDB 2009). No information was found on levels of diazoaminobenzene production in the United States. Diazoaminobenzene was available from five U.S. suppliers in 2009 (ChemSources 2009). U.S. imports of diazoaminobenzene and p-aminoazobenzenedisulfonic acid (combined category) totaled 34,877 lb in 2008 (USITC 2009).

## Exposure

The general population may be exposed to diazoaminobenzene through ingestion of products containing dyes or colorants or dermal exposure to such products. A 1977 study by the National Academy of Sciences reported average daily intakes of 43 mg for yellow no. 5 and 37 mg for yellow no. 6 (Feingold 2002). Thus, theoretical maximum average daily exposures to diazoaminobenzene are approximately 1.7 ng for yellow no. 5 and 1.5 ng for yellow no. 6, based on its maximum allowable levels in colorants under U.S. Food and Drug Administration regulations. Occupational exposure to diazoaminobenzene could occur from its use as a chemical intermediate and polymer additive.

## Regulations

### Department of Transportation (DOT)

Toxic dyes and toxic dye intermediates are considered hazardous materials, and special requirements have been set for marking, labeling, and transporting these materials.

### Food and Drug Administration (FDA)

The maximum level of diazoaminobenzene in color additives is 40 ppb for FD&C yellow no. 5 and no. 6 and 125 ppb for D&C red no. 33.

## References

Akron. 2009. The Chemical Database. Akron, OH: The Department of Chemistry at the University of Akron; http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
Bolle M, Luther K, Troe J, Ihlemann J, Gerhardt H. 1990. Photochemically assisted laser ablation of doped polymethyl-methacrylate. Appl Surf Sci. 46:279–283. 10.1016/0169-4332(90)90156-T
Bordelon NR, Chhabra R, Bucher JR. 2005. A review of evidence from short-term studies leading to the prediction that diazoaminobenzene (1,3-diphenyltriazine) is a carcinogen. J Appl Toxicol 25(6):514-521. 10.1002/jat.1087 10.1002/jat.1087
ChemIDplus. 2009. ChemIDplus Advanced. Bethesda, MD: National Library of Medicine; http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources. 2009. Chem Sources - Chemical Search. Pendleton, SC: Chemical Sources International; http://www.chemsources.com/chemonline.html and search on diazoaminobenzene.
FDA. 2010. Color Certification Reports. White Oak, MD: U.S. Food and Drug Administration; https://www.fda.gov/ForIndustry/ColorAdditives/ColorAdditiveInventories/ucm115641.htm
Feingold. 2002. National Academy of Sciences 1977 Survey of the Amount of Certified FD&C Colorants Consumed. Indianapolis, IN Feingold Association of the United States. https://www.feingold.org/NAS.pdf
HSDB. 2009. Hazardous Substances Data Bank. Bethesda, MD: National Library of Medicine; http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
Kadiiska MB, De Costa KS, Mason RP, Mathews JM. 2000. Reduction of 1,3-diphenyl-1-triazene by rat hepatic microsomes, by cecal microflora, and in rats generates the phenyl radical metabolite: an ESR spin-trapping investigation. Chem Res Toxicol 13(11):1082-1086. 10.1021/tx000098v 10.1021/tx000098v
Lewis RJ. 1997. Hawley’s Condensed Chemical Dictionary. New York, NY: Van Nostrand Reinhold.
Mathews JM, De Costa KS. 1999. Absorption, metabolism, and disposition of 1,3-diphenyl-1-triazene in rats and mice after oral, i.v., and dermal administration. Drug Metab Dispos. 27(12):1499–1504. 10570033
NTP. 2002. NTP Report on the Metabolism, Toxicity, and Predicted Carcinogenicity of Diazoaminobenzene (CAS No. 136-35-6). Research Triangle Park, NC: National Toxicology Program. Technical Report Series no. 073.
Ress NB, Witt KL, Xu J, Haseman JK, Bucher JR. 2002. Micronucleus induction in mice exposed to diazoaminobenzene or its metabolites, benzene and aniline: implications for diazoaminobenzene carcinogenicity. Mutat Res 521(1-2):201-208. 10.1016/S1383-5718(02)00241-3 10.1016/S1383-5718(02)00241-3
Smith WB, Ho OC. 1990. Application of the isoamyl nitrite-diiodomethane route to aryl iodides. J Org Chem. 55:2543–2545. 10.1021/jo00295a056
USITC. 2009. USITC Interactive Tariff and Trade DataWeb. Washington, DC: United States International Trade Commission; https://dataweb.usitc.gov/scripts/user_set.asp and search on HTS no. 2927000300.
Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K, Speck W. 1987. Salmonella mutagenicity tests: III. Results from the testing of 255 chemicals. Environ Mutagen. 9:1–109. 10.1002/em.2860090602 3552650