# Collaborators

- National Institute of Environmental Health Sciences, National Toxicology Program, Research Triangle Park, North Carolina, USA
  Rick Woychik, Ph.D.
- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Ruth M. Lunn, Dr.P.H. (Project Leader)
  Brian R. Berridge, D.V.M., Ph.D., DACVP
  John R. Bucher, Ph.D., DABT
  Gloria Jahnke, D.V.M., DABT
  Suril S. Mehta, Dr.P.H.
  H.S. Amy Wang, Ph.D.
  Mary S. Wolfe, Ph.D.
- Integrated Laboratory Systems, Inc., Research Triangle Park, North Carolina, USA
  Sanford Garner, Ph.D.
  Whitney Arroyave, Ph.D.
  Stanley Atwood, M.S., DABT
  Andrew Ewens, Ph.D., DABT
  Alton Peters, M.S.
  Pamela Schwingl, Ph.D.