# p-Chloro-o-toluidine and Its Hydrochloride

CAS Nos. 95-69-2 and 3165-93-3

Reasonably anticipated to be human carcinogens

First listed in the Eighth Report on Carcinogens (1998)

Also known as 4-chloro-o-toluidine or 4-chloro-2-methylaniline

Figure 1

Chemical Structure of p-Chloro-o-toluidine

## Carcinogenicity

p-Chloro-o-toluidine and its hydrochloride salt are reasonably anticipated to be human carcinogens based on limited evidence of carcinogenicity from studies in humans and evidence of carcinogenicity from studies in experimental animals.

### Cancer Studies in Humans

There is limited evidence for the carcinogenicity of p-chloro-o-toluidine from epidemiological studies in humans. Three cohort studies found high relative risks for urinary-bladder cancer among workers exposed to p-chloro-o-toluidine; however, confounding by co-exposure to other potential urinary-bladder carcinogens could not be ruled out. Documented human exposure to p-chloro-o-toluidine has occurred primarily in the dye and synthetic-chemical industries (IARC 2000). Between 1982 and 1990, 7 cases of urinary-bladder cancer were detected in a group of 49 German and Danish workers who were involved in producing the insecticide chlordimeform from p-chloro-o-toluidine on an irregular basis for an average of 18 years (Popp et al. 1992). The incidence of urinary-bladder tumors in this group was significantly higher than the expected incidence based on national or regional cancer registries. A brain tumor also occurred in one of the seven workers with urinary-bladder cancer. Exposure levels were not documented, but exposure to p-chloro-o-toluidine from 1980 to 1986 was demonstrated analytically by monitoring of the workers’ urine, where it was reported to be present at minimal levels (concentrations were not reported). There was some evidence that the cohort handled other chemicals (including o-chloroaniline); however, none of the resulting exposures were quantified by chemical analysis at the time. In other studies, workers were exposed to p-chloro-o-toluidine and numerous other compounds, several of which are potential carcinogens. No exposure levels were documented, and the exposures occurred before 1980, when modern industrial-hygiene standards were implemented (Hogan 1993; IARC 1990; Ott and Langner 1983; Stasik 1988).

### Cancer Studies in Experimental Animals

Dietary administration of p-chloro-o-toluidine hydrochloride caused benign or malignant blood-vessel tumors (hemangioma or hemangiosarcoma) in the spleen and adipose tissue in mice of both sexes, in two different mouse strains (IARC 1990; NCI 1979; Weisburger et al. 1978).

### Studies on Mechanisms of Carcinogenesis

p-Chloro-o-toluidine caused genetic damage in a variety of prokaryotic and mammalian in vitro and in vivo test systems (Göggelmann et al. 1996; IARC 1990). p-Chloro-o-toluidine binding to DNA was demonstrated in vitro with calf thymus DNA and in vivo following administration to mice and rats by intraperitoneal injection (Bentley et al. 1986; Hill et al. 1979; IARC 2000). In organs from animals exposed to p-chloro-o-toluidine, DNA breakage was detected by single-cell gel electrophoresis (comet assay) in mouse liver, urinary bladder, lung, and brain and in rat liver and kidney (Sekihashi et al. 2002).

## Properties

p-Chloro-o-toluidine is a chlorinated aromatic amine that exists as a grayish-white crystalline solid or leaflet, and p-chloro-o-toluidine hydrochloride is a buff-colored or light-pink powder at room temperature. The base compound is practically insoluble in water or carbon tetrachloride but is soluble in ethanol or dilute acid solutions. It is stable under normal temperatures and pressures (Akron 2009). Physical and chemical properties of p-chloro-o-toluidine are listed in Table 1. No physical and chemical properties for the hydrochloride were found except its molecular weight of 178.1 and melting range of 265°C to 270°C (IARC 2000; Weisburger et al. 1978).

Table 1 Properties of p-Chloro-o-toluidine

Property | Information
Molecular weight | 141.6^a^
Melting point | 30°C^a^
Boiling point | 241°C^a^
Log K_ow_ | 2.27^b^
Water solubility | 0.95 g/L at 25°C^b^
Vapor pressure | 0.041 mm Hg at 25°C^b^
Vapor density relative to air | 4.9^a^
Dissociation constant (pK_a_) | 3.85 at 25°C^a^

Sources: ^a^HSDB (2009), ^b^ChemIDplus (2009).

## Use

p-Chloro-o-toluidine and its hydrochloride salt are used in manufacturing azo dyes for cotton, silk, acetate, and nylon and as intermediates in the production of the dyes C.I. 12800, pigment red 7, and pigment yellow 49 (IARC 1990; 2000). p-Chloro-o-toluidine has also been used since the 1960s in the manufacture of the pesticide (insecticide and acaricide) chlordimeform. It is believed that chlordimeform is no longer produced or used worldwide (IARC 1990).

## Production

Commercial production of p-chloro-o-toluidine began in Germany in 1924 and was first reported in the United States in 1939 (IARC 1990; 2000). In 2009, p-chloro-o-toluidine was produced by two manufacturers in China and one in India (SRI 2009); worldwide, p-chloro-o-toluidine free base was available from 25 suppliers and the hydrochloride from 5 suppliers (ChemSources 2009). In 1976, U.S. imports of the free base were 25,000 lb (NCI 1979). U.S. imports in a category of substances including p-chloro-o-toluidine (toluidines and their salts) were 680,000 kg (1.5 million pounds) in 1995, reached a high of 708,000 kg (1.6 million pounds) in 2000, and declined to 209,000 kg (461,000 lb) in 2004. No imports in this category were reported from 1989 to 1994. From 1989 to 2004, U.S. exports in this category ranged from a high of 9.8 million kilograms (22 million pounds) in 1992 to a low of 1.8 million kilograms (3.7 million pounds) in 2002 (USITC 2009). Reports filed in 1986 and 1990 under the U.S. Environmental Protection Agency’s Toxic Substances Control Act Inventory Update Rule indicated that U.S. production plus imports of p-chloro-o-toluidine totaled 10,000 to 500,000 lb. No inventory update reports for p-chloro-o-toluidine were filed in 1994 or 1998, and reports in 2002 indicated a quantity of less than 10,000 lb (EPA 2004).

## Exposure

The routes of potential human exposure to p-chloro-o-toluidine are inhalation, ingestion, and dermal contact. The general population can be exposed to p-chloro-o-toluidine from the use of products that contain it as an impurity; for example, p-chloro-o-toluidine was found in five samples of finger paints tested in a study in Spain (Garrigós et al. 2000). p-Chloro-o-toluidine hydrochloride has also been found as an impurity in the pesticide chlordimeform (IARC 2000).

p-Chloro-o-toluidine could be released to the environment from decomposition of chlordimeform. As of 2000, chlordimeform was not believed to be produced or used anywhere in the world (IARC 2000). Previously, p-chloro-o-toluidine was isolated and identified in field samples of plant materials treated with chlordimeform. It was measured in young bean leaves at concentrations of less than 0.1 to 0.2 ppm (mg/kg), in grape stems at 0.02 to 0.3 ppm, in a mixture of grape stems and berries at 0.02 to 0.05 ppm, and in prunes and apples at less than 0.04 ppm (Kossmann et al. 1971). p-Chloro-o-toluidine was also reported to be metabolized from chlordimeform by enzymes present in the leaves of apple seedlings and in cotton plants (IARC 1990; 2000). In an experimental field application, residual concentrations of p-chloro-o-toluidine were found in rice grains at 3 to 61 ppb (μg/kg), in straw parts at 80 to 7,200 ppb, in the upper layer of soil (0 to 5 cm) at 2 to 68 ppb, and in the lower layer of soil (5 to 10 cm) at trace levels to 20 ppb. In another experimental field application of chlordimeform, no residues of p-chloro-o-toluidine were detected in rice grains or husks tested 20 to 55 days after pesticide application (IARC 1990). Mammals (including dogs, rats, goats, and humans) also metabolize chlordimeform to p-chloro-o-toluidine.

If p-chloro-o-toluidine is released to air, it will exist as a vapor and degrade by direct photolysis or photochemically produced hydroxyl radicals, with an estimated half-life of 9 hours. If it is present in water, it will slowly volatilize. It is expected to be moderately mobile in mainly inorganic soils but to bind tightly to soils with high humus or organic-matter content. p-Chloro-o-toluidine will biodegrade slowly in soil or water and has a low potential for bioaccumulation (HSDB 2009).

p-Chloro-o-toluidine has been measured in the urine of workers exposed to chlordimeform; however, no data were found on the levels detected (IARC 1983; 1990). Occupations with the greatest potential for exposure to p-chloro-o-toluidine include manufacturers of pigments, dyes, and chlordimeform (IARC 2000). Exposures to p-chloro-o-toluidine were reported to occur during the charging of mixing vats and at the basification stage at a chemical purification facility in England, at a batch-operated chemical processing plant in the United States, and during its production and processing at a facility in Germany. Data on exposure levels were not provided for any of these studies (IARC 1990). The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that 250 workers (health-services workers and chemists, but not biochemists), all of whom were women, potentially were exposed to p-chloro-o-toluidine and that 682 workers (health-services and clinical-laboratory workers and health aides, but not nursing aides), including 425 women, potentially were exposed to p-chloro-o-toluidine hydrochloride (NIOSH 1990).

## Regulations

### Department of Transportation (DOT)

p-Chloro-o-toluidine hydrochloride is considered a hazardous material, and special requirements have been set for marking, labeling, and transporting this material.

### Environmental Protection Agency (EPA)

#### Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 100 lb for p-chloro-o-toluidine hydrochloride.

#### Emergency Planning and Community Right-to-Know Act

Toxics Release Inventory: p-Chloro-o-toluidine is a listed substance subject to reporting requirements.

#### Resource Conservation and Recovery Act

Listed Hazardous Waste: Waste code for which the listing is based wholly or partly on the presence of p-chloro-o-toluidine hydrochloride = U049.

## References

Akron. 2009. The Chemical Database. The Department of Chemistry at the University of Akron; Last accessed: 4/29/09. http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
Bentley P, Bieri F, Muecke W, Waechter F, Stäubli W. 1986. Species differences in the toxicity of p-chloro-o-toluidine to rats and mice. Covalent binding to hepatic macromolecules and hepatic non-parenchymal cell DNA and an investigation of effects upon the incorporation of [^3^H] thymidine into capillary endothelial cells. Chem Biol Interact. 57(1):27–40. 10.1016/0009-2797(86)90046-3 2418987
ChemIDplus. 2009. ChemIDplus Advanced. National Library of Medicine; Last accessed: 4/29/09. http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources. 2009. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 4/29/09. http://www.chemsources.com/chemonline.html and search on chlorotoluidine.
EPA. 2004. Non-confidential IUR Production Volume Information. U.S. Environmental Protection Agency; https://www.epa.gov/oppt/iur/tools/data/2002-vol.html and search on CAS number.
Garrigós MC, Reche F, Pernías K, Jiménez A. 2000. Optimization of parameters for the analysis of aromatic amines in finger-paints. J Chromatogr A. 896(1-2):291–298. 10.1016/S0021-9673(00)00742-1 11093664
Göggelmann W, Bauchinger M, Kulka U, Schmid E. 1996. Genotoxicity of 4-chloro-o-toluidine in Salmonella typhimurium, human lymphocytes and V79 cells. Mutat Res. 370(1):39–47. 10.1016/S0165-1218(96)90125-1 8830805
Hill DL, Shih TW, Struck RF. 1979. Macromolecular binding and metabolism of the carcinogen 4-chloro-2-methylaniline. Cancer Res. 39(7 Pt 1):2528–2531. 445453
Hogan TJ. 1993. Case study “carcinogens:” The MBOCA TLV example. Am Ind Hyg Assoc J. 54(8):458–463. 10.1080/15298669391354964 8213489
HSDB. 2009. Hazardous Substances Data Bank. National Library of Medicine; Last accessed: 3/22/09. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1983. Chlordimeform. In Miscellaneous Pesticides. IARC Monographs on the Evaluation of the Carcinogenic Risk of Chemicals to Humans, vol. 30. Lyon, France: International Agency for Research on Cancer. pp. 61–72.
IARC. 1990. para-Chloro-ortho-toluidine and its strong acid salts. In Some Flame Retardants and Textile Chemicals, and Exposures in the Textile Manufacturing Industry. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 48. Lyon, France: International Agency for Research on Cancer. pp. 123–137.
IARC. 2000. 4-Chloro-ortho-toluidine. In Some Industrial Chemicals. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 77. Lyon, France: International Agency for Research on Cancer. pp. 323–339.
Kossmann K, Geissbuhler H, Boyd VF. 1971. Specific determination of chlorphenamidine (N'-(4-chloro-o-tolyl)-N,N-dimethylformamidine) in plants and soil material by colorimetry and thin-layer and electron capture gas chromatography. J Agric Food Chem. 19(2):360–364. 10.1021/jf60174a029 5546166
NCI. 1979. Bioassay of 4-Chloro-o-Toluidine Hydrochloride for Possible Carcinogenicity. Bethesda, MD: National Institutes of Health. Technical Report Series no. 165. DHEW (NIH) Publication No. 79-1721.
NIOSH. 1990. National Occupational Exposure Survey (1981-83). National Institute for Occupational Safety and Health; https://www.cdc.gov/noes/noes1/t0066sic.html, https://www.cdc.gov/noes/noes1/x1279sic.html
Ott MG, Langner RR. 1983. A mortality survey of men engaged in the manufacture of organic dyes. J Occup Med. 25(10):763–768. 10.1097/00043764-198310000-00018 6631562
Popp W, Schmieding W, Speck M, Vahrenholz C, Norpoth K. 1992. Incidence of bladder cancer in a cohort of workers exposed to 4-chloro-o-toluidine while synthesising chlordimeform. Br J Ind Med. 49(8):529–531. 10.1136/oem.49.8.529 1515344
Sekihashi K, Yamamoto A, Matsumura Y, Ueno S, Watanabe-Akanuma M, Kassie F, Knasmüller S, Tsuda S, Sasaki YF. 2002. Comparative investigation of multiple organs of mice and rats in the comet assay. Mutat Res. 517(1-2):53–75. 10.1016/S1383-5718(02)00034-7 12034309
SRI. 2009. Directory of Chemical Producers. Menlo Park, CA: SRI Consulting. Database edition; Last accessed: 4/29/09.
Stasik MJ. 1988. Carcinomas of the urinary bladder in a 4-chloro-o-toluidine cohort. Int Arch Occup Environ Health. 60(1):21–24. 10.1007/BF00409374 3350600
USITC. 2009. USITC Interactive Tariff and Trade DataWeb. United States International Trade Commission; https://dataweb.usitc.gov/scripts/user_set.asp and search on HTS no. 292143.
Weisburger EK, Russfield AB, Homburger F, Weisburger JH, Boger E, Van Dongen CG, Chu KC. 1978. Testing of twenty-one environmental aromatic amines or derivatives for long-term toxicity or carcinogenicity. J Environ Pathol Toxicol. 2(2):325–356. 84039