# Chloroprene

CAS No. 126-99-8

Reasonably anticipated to be a human carcinogen

First listed in the Ninth Report on Carcinogens (2000)

Also known as 2-chloro-1,3-butadiene

Figure 1

Chemical Structure of Chloroprene

## Carcinogenicity

Chloroprene is reasonably anticipated to be a human carcinogen based on evidence of carcinogenicity from studies in experimental animals.

### Cancer Studies in Experimental Animals

Inhalation exposure to chloroprene caused tumors at several different tissue sites in mice and rats. It caused lung tumors (alveolar/bronchiolar adenoma and/or carcinoma) in mice of both sexes and in male rats; kidney tumors in rats of both sexes and in male mice (renal-tubule adenoma); and mammary-gland tumors in female rats (fibroadenoma) and mice. In rats of both sexes, it also caused tumors of the oral cavity (squamous-cell papilloma and carcinoma) and thyroid gland (follicular-cell adenoma or carcinoma). In mice, it also caused tumors of the forestomach (squamous-cell papilloma), Harderian gland (adenoma or carcinoma), and blood vessels (hemangioma and hemangiosarcoma) in both sexes and tumors of the liver (hepatocellular adenoma and carcinoma), Zymbal gland (carcinoma), skin (sarcoma), and mesentery (sarcoma) in females (NTP 1998).

### Cancer Studies in Humans

Data from two early epidemiological studies suggested that occupational exposure to chloroprene may increase the risks of cancer of the liver, lung, and digestive and lymphohematopoietic systems (Li et al. 1989; Pell 1978). Since chloroprene was listed in the Ninth Report on Carcinogens, additional epidemiological studies have been identified. Mortality from leukemia and liver cancer was significantly increased among shoe-manufacturing workers, and liver-cancer incidence and mortality were significantly increased among chloroprene-production workers (Bulbulyan et al. 1998; Bulbulyan et al. 1999). However, two other cohort studies of chloroprene-production workers found no excess of liver cancer (Colonna and Laydevant 2001; Marsh et al. 2007a; 2007b). These two studies reported increased risks of lung or respiratory cancer; however, the risk estimates were not statistically significant or related to exposure category in the small cohort study (Colonna and Laydevant 2001) and were significantly elevated in only one of several plants in the large multi-plant study (Marsh et al. 2007a; 2007b).

### Studies on Mechanisms of Carcinogenesis

Chloroprene (the 2-chloro analogue of 1,3-butadiene) caused all of the same types of tumors that 1,3-butadiene caused in mice except for lymphoma and tumors of the preputial gland and ovary (NTP 1998).

In vitro metabolism of chloroprene by mouse, rat, hamster, and human microsomes produced (1-chloroethenyl)oxirane, an epoxide that is thought to react with DNA and can be further metabolized by hydrolysis and glutathione conjugation (Himmelstein et al. 2001). However, many studies on the genotoxicity of chloroprene have given negative results, and positive results from earlier studies were attributed to differences in the age and purity of the chloroprene samples (NTP 1998; Westphal et al. 1994). The mutagenicity of chloroprene in bacteria (Bartsch et al. 1975; Bartsch et al. 1979) was considered to be due to cyclic dimers that accumulate in aged samples (Westphal et al. 1994).

At the same exposure concentrations as used in the inhalation-exposure studies of cancer in mice, chloroprene did not cause sister chromatid exchange or chromosomal aberrations in mouse bone-marrow cells, nor did it increase the frequency of micronucleated erythrocytes in peripheral blood (Tice et al. 1988). During another inhalation-exposure study in mice and rats, chloroprene caused dominant lethal mutations in both species and chromosomal aberrations in mouse bone marrow cells (Sanotskii 1976). However, despite the largely negative findings for genotoxicity, chloroprene-induced lung and Harderian-gland tumors from mice had a high frequency of unique mutations of the K-ras proto-oncogene (NTP 1998). In addition, occupational-exposure studies reported increased frequencies of chromosomal aberrations in the lymphocytes of workers (IARC 1979).

## Properties

Chloroprene is a halogenated alkene that exists at room temperature as a clear colorless liquid with a pungent ether-like odor. It is practically insoluble in water, soluble in alcohol, and miscible with acetone, benzene, and ethyl ether. It is highly flammable and polymerizes on standing, making it unstable in the environment (Akron 2009). Physical and chemical properties of chloroprene are listed in Table 1.

Table 1 Properties of Chloroprene

Property | Information
Molecular weight | 88.5^a^
Specific gravity | 0.956 at 20°C/4°C^a^
Melting point | −130°C^a^
Boiling point | 59°C^a^
Log K_ow_ | 2.53^b^
Water solubility | 0.875 g/L at 25°C^b^
Vapor pressure | 215 mm Hg at 25°C^a^
Vapor density relative to air | 3^a^

Sources: ^a^HSDB (2009), ^b^ChemIDplus (2009).

## Use

The only commercial use identified for chloroprene is as a monomer in the production of the elastomer polychloroprene (neoprene), a synthetic rubber used in the production of automotive and mechanical rubber goods, adhesives, caulks, flame-resistant cushioning, construction materials, fabric coatings, fiber binding, and footwear. Other uses of this polymer include applications requiring chemical, oil, or weather resistance or high gum strength. The U.S. Food and Drug Administration permits the use of chloroprene as a component of adhesives used in food packaging and also permits the use of polychloroprene in products intended for use with food (IARC 1979; 1999; NTP 1998).

## Production

In 2009, chloroprene was produced by one manufacturer each in the United States and China and two manufacturers in Europe (SRI 2009) and was available from eleven suppliers, including seven U.S. suppliers (ChemSources 2009). Under the U.S. Environmental Protection Agency’s Toxic Substances Control Act Chemical Data Reporting Rule, U.S. production plus imports of chloroprene were reported to be in the range of 50 million to 100 million pounds in 2015 (EPA 2016).

## Exposure

The routes of human exposure to chloroprene are inhalation, ingestion, and dermal contact. Chloroprene is not known to occur naturally in the environment (IARC 1999). The main sources of environmental releases are effluent and emissions from facilities that use chloroprene to produce polychloroprene elastomers. According to EPA’s Toxics Release Inventory, environmental releases of chloroprene have decreased steadily from a high of over 2 million pounds in 1988 (the year reporting started). In 2007, two facilities reported chloroprene releases of over 275,000 lb, and seven facilities reported releases of 1,300 lb or less, almost all to air (TRI 2009). When released to air, chloroprene reacts with photochemically generated hydroxyl radicals, with a half-life of 18 hours, and smaller amounts are removed by reaction with ozone, with a half-life of 10 days. Based on the Henry’s law constant and octanol-water partition coefficient, chloroprene is expected to be removed from water and damp soil primarily by volatilization. If released to water, chloroprene is expected to volatilize from the surface, with a half-life of 3 hours from streams and 4 days from lakes. It will not adsorb to sediment or suspended solids or bioaccumulate in aquatic organisms. If released to soil, chloroprene is expected to volatilize or may leach into groundwater (HSDB 2009). In 1991, EPA’s Urban Air Toxics Monitoring Program identified chloroprene in 88 of 349 samples (25.2%), at concentrations ranging from 0.01 to 1.78 ppb (0.036 to 6.44 μg/m^3^). The results were similar in 1996, but in 2000 and 2005, chloroprene was detected in only one sample.

The main source of occupational exposure to chloroprene is the manufacture of chloroprene or polychloroprene (NTP 1998). In 1977, it was estimated that 2,500 to 3,000 workers were exposed to chloroprene during its manufacture and polymerization (Infante 1977). Chloroprene monomer is manufactured in a closed system, which is then used on site to make the polymer. The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that 17,700 workers, including 650 women, potentially were exposed to chloroprene or polychloroprene (NIOSH 1990). Time-weighted 8-hour average concentrations at three facilities (two in the United States and one in Northern Ireland) from 1975 to 1992 were 1 ppm in all but three samples, and chloroprene concentrations in the monomer manufacturing phase were below 1.8 ppm in all samples (Hall et al. 2007). During the polymer manufacturing phase, chloroprene concentrations were as high as 4.66 ppm in Northern Ireland and 3.42 ppm in the United States. By 1992, concentrations in all polymer facilities were lower (1.4 and 0.53 ppm in the United States and 0.37 ppm in Northern Ireland).

## Regulations

### Department of Transportation (DOT)

Chloroprene is considered a hazardous material, and special requirements have been set for marking, labeling, and transporting this material.

### Environmental Protection Agency (EPA)

#### Clean Air Act

National Emission Standards for Hazardous Air Pollutants: Listed as a hazardous air pollutant.

New Source Performance Standards: Manufacture is subject to certain provisions for the control of volatile organic compound emissions.

#### Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 100 lb.

#### Emergency Planning and Community Right-to-Know Act

Toxics Release Inventory: Listed substance subject to reporting requirements.

#### Resource Conservation and Recovery Act

Listed as a hazardous constituent of waste.

### Occupational Safety and Health Administration (OSHA, Dept. of Labor)

While this section accurately identifies OSHA’s legally enforceable PELs for this substance in 2018, specific PELs may not reflect the more current studies and may not adequately protect workers.

Permissible exposure limit (PEL) = 25 ppm (90 mg/m^3^).

Potential for dermal adsorption.

## Guidelines

### American Conference of Governmental Industrial Hygienists (ACGIH)

Threshold limit value – time-weighted average (TLV-TWA) = 10 ppm (36 mg/m^3^).

Potential for dermal absorption.

### National Institute for Occupational Safety and Health (NIOSH, CDC, HHS)

Ceiling recommended exposure limit = 1 ppm (3.6 mg/m^3^) (15-min exposure).

Immediately dangerous to life and health (IDLH) limit = 300 ppm (1,086 mg/m^3^).

Listed as a potential occupational carcinogen.

## References

Akron. 2009. The Chemical Database. The Department of Chemistry at the University of Akron; Last accessed: 5/09. http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
Bartsch H, Malaveille C, Barbin A, Planche G. 1979. Mutagenic and alkylating metabolites of halo-ethylenes, chlorobutadienes and dichlorobutenes produced by rodent or human liver tissues. Evidence for oxirane formation by P450-linked microsomal mono-oxygenases. Arch Toxicol. 41(4):249–277. 10.1007/BF00296896 373707
Bartsch H, Malaveille C, Montesano R, Tomatis L. 1975. Tissue-mediated mutagenicity of vinylidene chloride and 2-chlorobutadiene in Salmonella typhimurium. Nature. 255(5510):641–643. 10.1038/255641a0 1094302
Bulbulyan MA, Changuina OV, Zaridze DG, Astashevsky SV, Colin D, Boffetta P. 1998. Cancer mortality among Moscow shoe workers exposed to chloroprene (Russia). Cancer Causes Control. 9(4):381–387. 10.1023/A:1008863516506 9794169
Bulbulyan MA, Margaryan AG, Ilychova SA, Astashevsky SV, Uloyan SM, Cogan VY, Colin D, Boffetta P, Zaridze DG. 1999. Cancer incidence and mortality in a cohort of chloroprene workers from Armenia. Int J Cancer. 81(1):31–33. 10.1002/(SICI)1097-0215(19990331)81:1<31::AID-IJC6>3.0.CO;2-T 10077148
ChemIDplus. 2009. ChemIDplus Advanced. National Library of Medicine; Last accessed: 5/20/09. http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources. 2009. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 6/23/09. http://www.chemsources.com/chemonline.html and search on chloroprene.
Colonna M, Laydevant G. 2001. A cohort study of workers exposed to chloroprene in the department of Isère, France. Chem Biol Interact. 135-136:505–514. 10.1016/S0009-2797(01)00185-5 11397409
EPA. 2016. Chemical Data Reporting Summary: 2-Chloro-1,3-Butadiene. U.S. Environmental Protection Agency; https://chemview.epa.gov/chemview and search on CAS number or substance name and select Manufacturing, Processing, Use, and Release Data Maintained by EPA and select Chemical Data Reporting Details.
Hall TA, Esmen NA, Jones EP, Basara H, Phillips ML, Marsh GM, Youk AO, Buchanich JM, Leonard RC. 2007. Chemical process based reconstruction of exposures for an epidemiological study. III. Analysis of industrial hygiene samples. Chem Biol Interact. 166(1-3):277–284. 10.1016/j.cbi.2006.09.004 17074311
Himmelstein MW, Carpenter SC, Hinderliter PM, Snow TA, Valentine R. 2001. The metabolism of beta-chloroprene: Preliminary in-vitro studies using liver microsomes. Chem Biol Interact. 135-136:267–284. 10.1016/S0009-2797(01)00214-9 11397396
HSDB. 2009. Hazardous Substances Data Bank. National Library of Medicine; Last accessed: 5/09. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1979. Chloroprene and polychloroprene. In Some Monomers, Plastics and Synthetic Elastomers, and Acrolein. IARC Monographs on the Evaluation of the Carcinogenic Risk of Chemicals to Humans, vol. 19. Lyon, France: International Agency for Research on Cancer. pp. 131–156.
IARC. 1999. Chloroprene. In Re-evaluation of Some Organic Chemicals, Hydrazine and Hydrogen Peroxide. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 71. Lyon, France: International Agency for Research on Cancer. pp. 227–250.
Infante PF. 1977. Mutagenic and carcinogenic risks associated with halogenated olefins. Environ Health Perspect. 21:251–254. 10.1289/ehp.7721251 565703
Li SQ, Dong QN, Liu YQ, Liu YG. 1989. Epidemiologic study of cancer mortality among chloroprene workers. Biomed Environ Sci. 2(2):141–149. 2590499
Marsh GM, Youk AO, Buchanich JM, Cunningham M, Esmen NA, Hall TA, Phillips ML. 2007 a. Mortality patterns among industrial workers exposed to chloroprene and other substances. I. General mortality patterns. Chem Biol Interact. 166(1-3):285–300. 10.1016/j.cbi.2006.08.011 16999943
Marsh GM, Youk AO, Buchanich JM, Cunningham M, Esmen NA, Hall TA, Phillips ML. 2007 b. Mortality patterns among industrial workers exposed to chloroprene and other substances. II. Mortality in relation to exposure. Chem Biol Interact. 166(1-3):301–316. 10.1016/j.cbi.2006.08.012 17007827
NIOSH. 1990. National Occupational Exposure Survey (1981-83). National Institute for Occupational Safety and Health; Last accessed: 4/7/05. https://www.cdc.gov/noes/noes1/18260sic.html
NTP. 1998. NTP Toxicology and Carcinogenesis Studies of Chloroprene (CAS No. 126-99-8) in F344/N Rats and B6C3F1 Mice (Inhalation Studies). Research Triangle Park, NC: National Toxicology Program. Technical Report Series no. 467.
Pell S. 1978. Mortality of workers exposed to chloroprene. J Occup Med. 20(1):21–29. 10.1097/00043764-197801000-00006 621591
Sanotskii IV. 1976. Aspects of the toxicology of chloroprene: Immediate and long-term effects. Environ Health Perspect. 17:85–93. 10.1289/ehp.761785 799963
SRI. 2009. Directory of Chemical Producers. Menlo Park, CA: SRI Consulting. Database edition; Last accessed: 5/09.
Tice RR, Boucher R, Luke CA, Paquette DE, Melnick RL, Shelby MD. 1988. Chloroprene and isoprene: Cytogenetic studies in mice. Mutagenesis. 3(2):141–146. 10.1093/mutage/3.2.141 3288837
TRI. 2009. TRI Explorer Chemical Report. U.S. Environmental Protection Agency; Last accessed: 5/09. https://www.epa.gov/triexplorer/ and select Chloroprene.
Westphal GA, Blaszkewicz M, Leutbecher M, Müller A, Hallier E, Bolt HM. 1994. Bacterial mutagenicity of 2-chloro-1,3-butadiene (chloroprene) caused by decomposition products. Arch Toxicol. 68(2):79–84. 10.1007/s002040050038 8179486