# Butylated Hydroxyanisole

CAS No. 25013-16-5

Reasonably anticipated to be a human carcinogen

First listed in the Sixth Annual Report on Carcinogens (1991)

Also known as BHA or (1,1-dimethylethyl)-4-methoxyphenol

2-BHA 3-BHA

Figure 1

Chemical Structure of Butylated Hydroxyanisole

## Carcinogenicity

Butylated hydroxyanisole (BHA) is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

### Cancer Studies in Experimental Animals

Dietary exposure to BHA caused benign and malignant tumors of the forestomach (papilloma and squamous-cell carcinoma) in rats of both sexes and in male mice and hamsters (IARC 1986; Masui et al. 1986). Since BHA was listed in the Sixth Annual Report on Carcinogens, an additional study in experimental animals has been identified. Dietary administration of BHA to fish (hermaphroditic Rivulus marmoratus) as larvae caused liver cancer (hepatocellular carcinoma) in the adult fish (Park et al. 1990).

### Cancer Studies in Humans

The data available from epidemiological studies are inadequate to evaluate the relationship between human cancer and exposure specifically to BHA. Since BHA was listed in the Sixth Annual Report on Carcinogens, one epidemiological study of BHA has been identified. A population-based nested case-control study of stomach cancer in men and women within the Netherlands Cohort Study of dietary intake found no increase in risk at typical levels of dietary intake of BHA (Botterweck et al. 2000).

## Properties

BHA is an antioxidant which exists at room temperature as a white or slightly yellow, waxy solid with a faint characteristic odor (IARC 1986). BHA in commercial use consists of a mixture of 3-tert-butyl-4-hydroxyanisole (3-BHA) and 2-tert-butyl-4-hydroxyanisole (2-BHA). BHA is insoluble in water, but is soluble in fats, oils, propylene glycol, petroleum ether, chloroform, and 50% alcohol. Physical and chemical properties of BHA are listed in Table 1.

Table 1 Properties of Butylated Hydroxyanisole

Property | Information
Molecular weight | 180.2^a^
Melting point | 48°C to 55°C^a^
Boiling point | 264°C to 270°C at 733 mm Hg^a^
Log K_ow_ | 3.5^b^
Water solubility | 0.213 g/L at 25°C^b^
Vapor pressure | 0.00248 mm Hg at 25°C^a^

Sources: ^a^ HSDB (2009), ^b^ ChemIDplus (2009).

## Use

BHA is used primarily as an antioxidant and preservative in food, food packaging, animal feed, and cosmetics, and in rubber and petroleum products (IARC 1986). Food-grade BHA contains over 85% 3-BHA and less than 15% 2-BHA, while cosmetic-grade BHA contains 90% 3-BHA and 8% 2-BHA. Since 1947, BHA has been added to edible fats and fat-containing foods for its antioxidant properties. It is also used in foods cooked or fried in animal oils, because of its high thermal stability and its ability to remain active in baked and fried foods (HSDB 2009). BHA is added to butter, lard, meats, cereals, baked goods, sweets, beer, vegetable oils, potato chips, snack foods, nuts and nut products, dehydrated potatoes, and flavoring agents. It is used in sausage, poultry and meat products, dry mixes for beverages and desserts, glazed fruits, chewing gum, active dry yeast, defoaming agents for beet sugar and yeast, and emulsion stabilizers for shortening (IARC 1986). BHA stabilizes the petroleum wax coatings of food packaging (HSDB 2009). BHA is considered by the U.S. Food and Drug Administration (FDA) to be generally recognized as safe when the antioxidant content does not exceed 0.02% by weight of the food’s total fat or oil content.

BHA is one of the primary antioxidants used in feeds, because it retards the oxidation of vitamin A, fats, and vegetable oils. It is an effective stabilizer for essential oils, paraffin, and polyethylenes (HSDB 2009). It is used as an antioxidizing agent in a biomaterial made from polyurethane and polyethylene oxide used to make mainline catheters (Silverstein et al. 1997). BHA is used as a preservative and antioxidant in pharmaceutical preparations and cosmetic formulations containing fats and oils. A 1981 FDA survey found that BHA was used in 3,217 of 21,279 cosmetic formulations; the majority (88%) of the reported concentrations did not exceed 0.1%. In that survey, use of BHA was highest in lipstick formulations (1,256 products), followed by eye-shadow products (410) (IARC 1986). For industrial use, BHA has largely been replaced by tert-butylhydroquinone.

## Production

In 2009, no producers of BHA were identified worldwide (SRI 2009), but it was available from 46 suppliers, including 18 U.S. suppliers (ChemSources 2009). No recent data on U.S. imports or exports of BHA were found. Reports filed under the U.S. Environmental Protection Agency’s Toxic Substances Control Act Inventory Update Rule indicated that U.S. production plus imports of BHA totaled 10,000 to 500,000 lb in 1986 and 2000, 1 million to 10 million pounds in 1996, and less than 500,000 lb in 2006 (EPA 2004; 2009).

## Exposure

Routes of human exposure to BHA are ingestion, inhalation, and dermal contact. In 1975, the estimated average daily intake of BHA in the diet was 4.3 mg (IARC 1986). Estimated annual U.S. use of BHA in food increased from 170,000 kg (374,000 lb) in 1960 to 300,000 kg (660,000 lb) between 1970 and 1982 (IARC 1986). Total reported annual use of BHA in the mid 1970s was 450 metric tons (990,000 lb) (Nicholas et al. 1978). The concentration of BHA in six samples of human adipose tissue ranged from 0.01 to 0.03 ppm (Conacher et al. 1986). Dermal exposure to BHA occurs from its use as an antioxidant in cosmetic products, especially lipstick and eye shadow (IARC 1986). BHA is also used as an antioxidant for some rubber and petroleum products, and it is a stabilizer for vitamin A (HSDB 2009).

Workers potentially are exposed to BHA in certain industries, including food producers, animal feed producers, livestock producers, cosmetic manufacturers, some petroleum workers, and rubber producers and those who handle the end products, such as tires. Fast-food service personnel who normally cook and serve fried and oily foods potentially are exposed to BHA at high levels; BHA is volatile at 150°C to 170°C (302°F to 338°F) and is readily lost from thermal processes that generate steam (Warner et al. 1986). The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that 89,673 workers, including 44,061 women, potentially were exposed to BHA. Most of these workers were in the Health Services (> 24,000 workers), Food (> 18,000 workers), and Chemical and Allied Products industries (> 13,000 workers) (NIOSH 1990).

## Regulations

### Food and Drug Administration (FDA)

BHA is generally recognized as safe for use in food when the total of antioxidants is not greater than 0.02% of fat or oil content.

BHA may be used as a food additive permitted for direct addition to food for human consumption as prescribed in 21 CFR 172 and 166.

BHA may be used in the manufacture of food packaging materials, with a limit of addition to food of 0.005%.

BHA may be used as an antioxidant in defoaming agents for processed foods, not to exceed 0.1% by weight of defoamer.

## References

Botterweck AA, Verhagen H, Goldbohm RA, Kleinjans J, van den Brandt PA. 2000. Intake of butylated hydroxyanisole and butylated hydroxytoluene and stomach cancer risk: Results from analyses in the Netherlands Cohort Study. Food Chem Toxicol 38(7):599-605. 10.1016/S0278-6915(00)00042-9 10.1016/S0278-6915(00)00042-9
ChemIDplus. 2009. ChemIDplus Advanced. Bethesda, MD: National Library of Medicine; http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources. 2009. Chem Sources - Chemical Search. Pendleton, SC: Chemical Sources International; Last accessed: 8/20/09. http://www.chemsources.com/chemonline.html and search on butylated hydroxyanisole.
Conacher HB, Iverson F, Lau PY, Page BD. 1986. Levels of BHA and BHT in human and animal adipose tissue: Interspecies extrapolation. Food Chem Toxicol 24(10-11):1159-1162. 10.1016/0278-6915(86)90302-9 10.1016/0278-6915(86)90302-9
EPA. 2004. Non-confidential IUR Production Volume Information. Washington, DC: U.S. Environmental Protection Agency; https://www.epa.gov/oppt/iur/tools/data/2002-vol.html and search on CAS number.
EPA. 2009. Non-confidential 2006 IUR Records by Chemical, Including Manufacturing, Processing and Use Information. Washington, DC: U.S. Environmental Protection Agency. https://cfpub.epa.gov/iursearch/2006_iur_natlcheminfo.cfm?id=4315
HSDB. 2009. Hazardous Substances Data Bank. Bethesda, MD: National Library of Medicine; http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1986. Some Naturally Occurring and Synthetic Food Components, Furocoumarins and Ultraviolet Radiation. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans. Vol. 40. Lyon, France: International Agency for Research on Cancer; Butylated hydroxyanisole (BHA); p. 123–159.
Masui T, Hirose M, Imaida K, Fukushima S, Tamano S, Ito N. 1986. Sequential changes of the forestomach of F344 rats, Syrian golden hamsters, and B6C3F_1_ mice treated with butylated hydroxyanisole. Jpn J Cancer Res. 77(11):1083–1090. 3098717
Nicholas PP, Luxeder AM, Brooks LA, Hammes PA. 1978. Antioxidants and antiozonants. In: Grayson M, editor. Kirk-Othmer Encyclopedia of Chemical Technology. Vol. 3. 3rd ed. New York, NY: John Wiley & Sons; p. 128–148.
NIOSH. 1990. National Occupational Exposure Survey (1981-83). Washington, DC: National Institute for Occupational Safety and Health; https://www.cdc.gov/noes/noes1/83660sic.html
Park EH, Chang HH, Cha YN. 1990. Induction of hepatic tumors with butylated hydroxyanisole in the self-fertilizing hermaphroditic fish Rivulus ocellatus marmoratus. Jpn J Cancer Res. 81(8):738–741. 10.1111/j.1349-7006.1990.tb02638.x 2118888
Silverstein B, Witkin KM, Frankos VH, Terr AI. 1997. Assessing the role of the biomaterial Aquavene in patient reactions to Landmark midline catheters. Regul Toxicol Pharmacol 25(1):60-67. 10.1006/rtph.1996.1057 10.1006/rtph.1996.1057
SRI. 2009. Directory of Chemical Producers, Database ed. Menlo Park, CA: SRI Consulting.
Warner CR, Brumley WC, Daniels DH. 1986. Reactions of antioxidants in foods. Food Chem Toxicol. 24(10-11):1015–1019. 10.1016/0278-6915(86)90282-6 3804107