# 1,3-Butadiene

CAS No. 106-99-0

Known to be a human carcinogen

First listed in the Fifth Annual Report on Carcinogens (1989)

Figure 1

Chemical Structure of 1,3-Butadiene

## Carcinogenicity

1,3-Butadiene is known to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in humans, including epidemiological and mechanistic studies. 1,3-Butadiene was first listed in the Fifth Annual Report on Carcinogens in 1989 as reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals. The listing was revised to known to be a human carcinogen in the Ninth Report on Carcinogens in 2000.

### Cancer Studies in Humans

A number of epidemiological studies have shown an association between occupational exposure to 1,3-butadiene and excess mortality from cancer of the lymphatic and hematopoietic systems. These include (1) a cohort study showing increased risk of lymphosarcoma and reticulosarcoma in workers who manufactured 1,3-butadiene monomer, (2) a study of styrene-butadiene rubber workers in eight plants in the United States and Canada showing increased risk of leukemia among production workers, and (3) a case-control study within the cohort of styrene-butadiene rubber workers showing a large excess of leukemia associated with exposure to 1,3-butadiene and not to styrene (IARC 1992). In addition, an excess of lymphosarcoma and reticulosarcoma was found among 1,3-butadiene production workers in a previously unstudied chemical plant (Ward et al. 1996). Excess deaths from leukemia were observed among long-term workers who were hired before 1960 and had worked in the three (of eight studied) styrene-butadiene rubber plants with the highest exposure to butadiene (standardized mortality ratio = 1.8 in comparison with the U.S. population). A second case-control study of styrene-butadiene rubber workers with lymphopoietic cancer (with a new set of controls for each case) confirmed the strong association and significant dose-response relationship between 1,3-butadiene exposure score and risk of leukemia (Matanoski et al. 1993). Finally, a follow-up study of styrene-butadiene rubber workers in the synthetic rubber industry also found a dose-response relationship between 1,3-butadiene exposure level and the occurrence of leukemia (Delzell et al. 1996; Delzell et al. 2006; Macaluso et al. 1996).

### Studies on Mechanisms of Carcinogenesis

1,3-Butadiene appears to cause tumors in humans and rodents through its metabolism to DNA-reactive epoxide intermediates, which cause genetic alterations in proto-oncogenes or tumor-suppressor genes (Melnick and Kohn 1995). Mouse, rat, and human liver microsomes have been shown to oxidize 1,3-butadiene to epoxybutene (Csanády et al. 1992) and to further oxidize the monoepoxide to diepoxybutane (Seaton et al. 1995). These metabolites form N′-alkylguanine adducts that have been detected in liver DNA of mice exposed to 1,3-butadiene and in the urine of a worker exposed to 1,3-butadiene. Activated K-ras oncogenes and inactivated tumor-suppressor genes observed in 1,3-butadiene-induced tumors in mice are analogous to genetic alterations frequently observed in a wide variety of human cancers. Dose-related increases in hprt mutations have been observed in lymphocytes isolated from mice exposed to 1,3-butadiene or its epoxide metabolites and in occupationally exposed workers. The mutational spectra for 1,3-butadiene and its epoxide metabolites at the hprt locus in mouse lymphocytes are similar to the mutational spectrum for ethylene oxide, an alkylating agent listed in the Report on Carcinogens as known to be a human carcinogen.

### Cancer Studies in Experimental Animals

There is sufficient evidence for the carcinogenicity of 1,3-butadiene from studies in experimental animals. Inhalation exposure to 1,3-butadiene caused benign or malignant tumors at several different tissue sites in rodents, including the hematopoietic system, heart (hemangiosarcoma), lung, forestomach, Harderian gland, preputial gland, liver, mammary gland, ovary, and kidney in mice (Huff et al. 1985; Melnick et al. 1990; NTP 1984) and the pancreas, testis, thyroid gland, mammary gland, uterus, and Zymbal gland in rats (Owen et al. 1987).

## Properties

1,3-Butadiene is an olefin which at room temperature is a colorless gas with a mild aromatic or gasoline odor. It is insoluble in water but soluble in ether, ethanol, acetone, and other organic solvents. It polymerizes readily, especially in the presence of oxygen; therefore, it is shipped and stored with an inhibitor to prevent this reaction (Akron 2009). It is also a dangerous fire hazard. Physical and chemical properties of 1,3-butadiene are listed in the following in Table 1.

Table 1 Properties of 1,3-Butadiene

Property | Information
Molecular weight | 54.1^a^
Density | 0.6149 g/cm^3^ at 25°C^a^
Melting point | −108.966°C^a^
Boiling point | −4.5°C at 760 mm Hg^a^
Log K_ow_ | 1.99^b^
Water solubility | 0.735 g/L at 20°C^a^
Vapor pressure | 2,110 mm Hg at 25°C^a^
Vapor density relative to air | 1.87^a^

Sources: ^a^ HSDB (2009), ^b^ ChemIDplus (2009).

## Use

1,3-Butadiene is used primarily as a monomer to manufacture many different types of polymers and copolymers and as a chemical intermediate to produce a number of important industrial chemicals. More than 75% of the 1,3-butadiene produced goes into synthetic rubber products (CEN 1986). The major uses include production of styrene-butadiene rubber (30% to 35%), polybutadiene rubber (20% to 22%), adiponitrile (12% to 15%), styrene-butadiene latex (10%), neoprene rubber (5% to 6%), acrylonitrile-butadiene-styrene resins (5% to 6%), and nitrile rubber (3%), exports (4%), and other uses, including production of specialty polymers (2% to 8%) (ATSDR 1993; IARC 1992). The major end-use products containing styrene-butadiene and polybutadiene are tires. Other products include latex adhesives, seals, hoses, gaskets, various rubber products, nylon carpet backings, paper coatings, paints, pipes, conduits, appliance and electrical equipment components, automotive parts, and luggage. The only major nonpolymer use is in the manufacture of adiponitrile, a nylon intermediate. Butadiene is also used in the manufacture of the fungicides captan and captafol (IARC 1992; Kirschner 1996; Morrow 1990).

## Production

1,3-Butadiene is isolated by distillation or extraction from crude butadiene, which is a by-product of ethylene production. Commercial production began in the 1930s (IARC 1992). In 2009, 11 U.S. producers and 12 U.S. suppliers of 1,3-butadiene were identified (ChemSources 2009; SRI 2009). In 2015, the U.S. Environmental Protection Agency (EPA) estimated that combined production and imports of butadiene were in the range of 1 to 5 billion pounds (EPA 2016), similar to annual production reported since the 1980s (ranging from 1.9 to 4.4 billion pounds) (CEN 1999; 2003; IARC 1992). Because U.S. demand for 1,3-butadiene has generally exceeded the domestic supply, imports have greatly exceeded exports (as shown in Table 2).

Table 2 Production, Imports, and Exports of 1,3-Butadiene

Category | Year | Quantity (lb)
Production + imports^a^ | 2015 | 1 to 5 billion
U.S. imports^b^ | 2017 | 629.2 million
U.S. exports^b^ | 2017 | 87.9 million

Sources: ^a^EPA (2016). ^b^ USITC (2018) (imports as “buta-1,3-diene and isomer thereof”).

## Exposure

Occupational exposure to 1,3-butadiene may occur through inhalation and, to a lesser extent, dermal contact (NTP 1984). The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that about 52,000 workers at 2,201 facilities, including 1,410 women, potentially were exposed to 1,3-butadiene (NIOSH 1990). This estimate does not include workers exposed to butadiene polymers and copolymers and is consistent with an earlier estimate of about 66,000 to 70,000 workers at 3,086 facilities reported in the National Occupational Hazard Survey (conducted from 1972 to 1974) (NIOSH 1976). Health hazard evaluation surveys conducted by the National Institute for Occupational Safety and Health at six facilities found air concentrations of 1,3-butadiene ranging from 0.06 to 39 ppm. Surveys conducted at many monomer, polymer, and end-user plants have reported concentrations ranging from below detection to 374 ppm (827 mg/m^3^). In most cases, 8-hour time-weighted-average concentrations were less than 10 ppm (< 22 mg/m^3^) (ATSDR 1993; IARC 1992). For the monomer industry as a whole, 1,3-butadiene concentrations were greater than 10 ppm (> 22 mg/m^3^) in 7.1% of the samples, 2 to 10 ppm (4 to 22 mg/m^3^) in 12.8%, 1 to 2 ppm (2 to 4 mg/m^3^) in 12.3% and less than 1 ppm (< 2 mg/m^3^) in 67.8%. The Occupational Safety and Health Administration permissible exposure limit is 1 ppm. For the polymer industry as a whole, the corresponding percentages for these four ranges were 3.3%, 7.7%, 3.3%, and 85.8%, respectively. The arithmetic mean exposure for personal full-shift exposures in the polymer plants was 1.14 ppm (2.57 mg/m^3^) (Fajen et al. 1993).

The primary route of potential exposure to 1,3-butadiene for the general population is inhalation. Some exposure may occur through ingestion of contaminated food or water or dermal contact; however, these routes of exposure are unlikely under most circumstances. 1,3-Butadiene is not a common contaminant of water supplies. Although some food packaging contains residual 1,3-butadiene, the available data indicate that it does not usually migrate to the food. Certain cooking oils, such as rapeseed oil (canola), release 1,3-butadiene when heated (Shields et al. 1995).

Most people are exposed to low levels of 1,3-butadiene in the air, because it is released to the environment during its production, use, storage, and disposal and is present in gasoline, automobile exhausts, and cigarette smoke. 1,3-Butadiene is emitted from petroleum refineries and from furnaces at secondary lead smelting facilities handling automotive lead-acid batteries that contain plastic battery separators or that have hard rubber casings (EPA 1996). Incomplete combustion of a variety of fuels forms 1,3-butadiene as a product. 1,3-Butadiene makes up 0.5% to 2% of the total organic gas emissions from most types of combustion (Ligocki et al. 1994). It can also be found in motor-vehicle exhaust emissions as a product of incomplete combustion of gasoline and diesel oil and from the thermal breakdown of plastics (ATSDR 1993; EPA 1996). Through modeling of dispersion from a typical freeway source in California, it was estimated that gasoline-fueled vehicles emit 0.011 g of 1,3-butadiene per mile (Cooper and Reisman 1992). 1,3-Butadiene also is formed naturally as a by-product of forest fires (HSDB 2009). Releases of 1,3-butadiene in sidestream cigarette smoke into the air have been variously estimated at 152 to 400 μg per cigarette (Ligocki et al. 1995). Calculations based on 400 μg per cigarette indicate that 1,3-butadiene concentrations in the homes of smokers would be increased by approximately 4 μg/m^3^, and concentrations in air at workplaces allowing smoking would be increased by 13 μg/m^3^ (Wallace 1991).

According to EPA’s Toxics Release Inventory, total industrial environmental releases of 1,3-butadiene declined from more than 7.7 million pounds in 1988 to about 1.8 million pounds in 2007, of which over 90% was released to air (TRI 2009). However, a nationwide 1,3-butadiene inventory (including vehicle emissions and emissions from manufacturing and producing facilities) calculated annual butadiene emissions to air to be 102 million kilograms (225 million pounds) in 1990 (Ligocki et al. 1994), considerably higher than EPA’s estimate of about 5.2 million pounds (2.4 million kilograms) for industrial emissions in the same year.

The median daily concentrations of 1,3-butadiene in U.S. ambient air samples collected from 1970 to 1987 were 0.29 ppb in urban areas (385 samples), 0.32 ppb in suburban areas (196 samples), and 0.1 ppb in rural areas (2 samples). The maximum 24-hour average concentrations of 1,3-butadiene reported for four U.S. cities in 2004 were 0.3 ppb for St. Louis, Missouri, 0.5 ppb for Chicago, Illinois, and Los Angeles, California, and 37.4 ppb for Houston, Texas (Clements et al. 2006). However, reported average daily concentrations of 1,3-butadiene in ambient air within a mile of petrochemical facilities have exceeded 100 ppb, and the highest hourly average concentrations have exceeded 900 ppb (ATSDR 1993). Volatilization of 1,3-butadiene from wastewaters of styrene-1,3-butadiene copolymer production at publicly owned treatment works has been calculated to be 21 tons per year (EPA 1996).

Occupational exposure to 1,3-butadiene may occur through inhalation and, to a lesser extent, dermal contact (NTP 1984). The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that about 52,000 workers at 2,201 facilities, including 1,410 women, potentially were exposed to 1,3-butadiene (NIOSH 1990). This estimate does not include workers exposed to butadiene polymers and copolymers and is consistent with an earlier estimate of about 66,000 to 70,000 workers at 3,086 facilities reported in the National Occupational Hazard Survey (conducted from 1972 to 1974) (NIOSH 1976). Health hazard evaluation surveys conducted by the National Institute for Occupational Safety and Health at six facilities found air concentrations of 1,3-butadiene ranging from 0.06 to 39 ppm. Surveys conducted at many monomer, polymer, and end-user plants have reported concentrations ranging from below detection to 374 ppm (827 mg/m^3^). In most cases, 8-hour time-weighted-average concentrations were less than 10 ppm (< 22 mg/m^3^) (ATSDR 1993; IARC 1992). For the monomer industry as a whole, 1,3-butadiene concentrations were greater than 10 ppm (> 22 mg/m^3^) in 7.1% of the samples, 2 to 10 ppm (4 to 22 mg/m^3^) in 12.8%, 1 to 2 ppm (2 to 4 mg/m^3^) in 12.3% and less than 1 ppm (< 2 mg/m^3^) in 67.8%. The Occupational Safety and Health Administration permissible exposure limit is 1 ppm. For the polymer industry as a whole, the corresponding percentages for these four ranges were 3.3%, 7.7%, 3.3%, and 85.8%, respectively. The arithmetic mean exposure for personal full-shift exposures in the polymer plants was 1.14 ppm (2.57 mg/m^3^) (Fajen et al. 1993).

## Regulations

### Department of Transportation (DOT)

Butadienes are considered hazardous materials, and special requirements have been set for marking, labeling, and transporting these materials.

### Environmental Protection Agency (EPA)

#### Clean Air Act

Mobile Source Air Toxics: Listed as a mobile source air toxic for which regulations are to be developed.

National Emission Standards for Hazardous Air Pollutants: Listed as a hazardous air pollutant.

New Source Performance Standards: Manufacture of 1,3-butadiene is subject to certain provisions for the control of volatile organic compound emissions.

Prevention of Accidental Release: Threshold quantity (TQ) = 10,000 lb.

Urban Air Toxics Strategy: Identified as one of 33 hazardous air pollutants that present the greatest threat to public health in urban areas.

Standards have been established for emissions of 1,3-butadiene from reformulated gasoline and motor vehicles.

#### Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 10 lb.

#### Emergency Planning and Community Right-to-Know Act

Toxics Release Inventory: Listed substance subject to reporting requirements.

### Occupational Safety and Health Administration (OSHA)

While this section accurately identifies OSHA’s legally enforceable PELs for this substance in 2018, specific PELs may not reflect the more current studies and may not adequately protect workers.

Permissible exposure limit (PEL) = 1 ppm.

Short-term exposure limit (STEL) = 5 ppm.

Comprehensive standards for occupational exposure to 1,3-butadiene have been developed.

## Guidelines

### American Conference of Governmental Industrial Hygienists (ACGIH)

Threshold limit value – time-weighted average (TLV-TWA) = 2 ppm.

Biological exposure index (BEI) (end of shift) = 2.5 mg/L for 1,2-dihydroxy-4-(N-acetylcysteinyl)-butane in urine; (timing not critical) = 2.5 pmol/g of hemoglobin for a mixture of N-(1-hydroxybutenyl)- and N-(2-hydroxybutenyl)-valine hemoglobin adducts in blood.

### National Institute for Occupational Safety and Health (NIOSH, CDC, HHS)

Immediately dangerous to life and health (IDLH) limit = 2,000 ppm.

Listed as a potential occupational carcinogen.

## References

Akron. 2009. The Chemical Database. Akron, OH: The Department of Chemistry at the University of Akron; http://ull.chemistry.uakron.edu/erd/ and search CAS number.
ATSDR. 1993. Toxicological Profile for 1,3-Butadiene. Atlanta, GA: Agency for Toxic Substances and Disease Registry. NTIS Accession No. P; p. B93–B110690.
CEN. 1986. Key Chemicals. Butadiene. Chem Eng News. 64(23):15.
CEN. 1999. Production. Modest gain. Chem Eng News. 77(26):34–39.
CEN. 2003. Production inches up in most countries. Chem Eng News. 81(27):51–61.
ChemIDplus. 2009. ChemIDplus Advanced. Bethesda, MD: National Library of Medicine; http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources.2009. Chem Sources - Chemical Search. Pendleton, SC: Chemical Sources International; http://www.chemsources.com/chemonline.html and search on butadiene.
Clements AL, Flatt VB, Fraser MP, Hamilton WJ, Ledvina PS, Mathur SK, Tamhane A, Ward JB. 2006. The Control of Air Toxics: Toxicology Motivation and Houston Implications. Houston, TX: Rice University Department of Civil and Environmental Engineering;. http://hydrology.rice.edu/ceve/fraser/FINAL%20MASTER.pdf.
Cooper FI, Reisman JI. 1992. The air toxic problem in California: A summary of CARB, BAAQMD and SCAQMD ambient air monitoring data. Proc Ann Meet Air Waste Manage Assoc 13:9.
Csanády GA, Guengerich FP, Bond JA. 1992. Comparison of the biotransformation of 1,3-butadiene and its metabolite, butadiene monoepoxide, by hepatic and pulmonary tissues from humans, rats and mice. J Carcinog 13(7):1143-1153. 10.1093/carcin/13.7.1143 10.1093/carcin/13.7.1143
Delzell E, Sathiakumar N, Graff J, Macaluso M, Maldonado G, Matthews R. 2006. An updated study of mortality among North American synthetic rubber industry workers. Res Rep Health Eff Inst. 132:1–63. 17326338
Delzell E, Sathiakumar N, Hovinga M, Macaluso M, Julian J, Larson R, Cole P, Muir DC. 1996. A follow-up study of synthetic rubber workers. Toxicology 113(1-3):182-189. 10.1016/0300-483X(96)03443-9 10.1016/0300-483X(96)03443-9
EPA. 1996. Locating and Estimating Air Emissions from Sources of 1,3-Butadiene. Research Triangle Park, NC: U.S. Environmental Protection Agency, Office of Air Quality Planning and Standards. Technical Report No. EPA-454/R-96-008.
EPA. 2016. Chemical Data Reporting Summary: 1,3-Butadiene. Washington, DC: U.S. Environmental Protection Agency. https://chemview.epa.gov/chemview and search on CAS number or substance name and select Manufacturing, Processing, Use, and Release Data Maintained by EPA and select Chemical Data Reporting Details.
Fajen JM, Lunsford RA, Roberts DR. 1993. Industrial exposure to 1,3-butadiene in monomer, polymer and end-user industries. IARC Sci Publ. (127):3–13. 8070876
HSDB. 2009. Hazardous Substances Data Bank. Bethesda, MD: National Library of Medicine; http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
Huff JE, Melnick RL, Solleveld HA, Haseman JK, Powers M, Miller RA. 1985. Multiple organ carcinogenicity of 1,3-butadiene in B6C3F_1_ mice after 60 weeks of inhalation exposure. Science 227(4686):548-549. 10.1126/science.3966163 10.1126/science.3966163
IARC. 1992. Occupational Exposures to Mists and Vapours from Strong Inorganic Acids and Other Industrial Chemicals. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans. Vol. 54. Lyon, France: International Agency for Research on Cancer; 1,3-Butadiene; p. 237–285.
Kirschner EM. 1996. Growth of top 50 chemicals slowed in 1995 from very high 1994 rate. Chem Eng News. 74(15):16–18, 20, 22. 10.1021/cen-v074n015.p016
Ligocki MP, Fieber JL, Ball JC, Pezda SA, Heuss JM, Paul RT, Wimette HJ. 1994. Projected emission trends and exposure issues for 1,3-butadiene. Proc Annu Meet Air Waste Manage Assoc 4B:18.
Ligocki MP, Gardner L, Tunggal HH, Heiken JG, Atkinson RD, Axelrad D. 1995. Cumulative exposure to air toxics: Indoor sources. Proc Annu Meet Air Waste Manage Assoc 3A:16.
Macaluso M, Larson R, Delzell E, Sathiakumar N, Hovinga M, Julian J, Muir D, Cole P. 1996. Leukemia and cumulative exposure to butadiene, styrene and benzene among workers in the synthetic rubber industry. Toxicology 113(1-3):190-202. 10.1016/0300-483X(96)03444-0 10.1016/0300-483X(96)03444-0
Matanoski G, Francis M, Correa-Villasenor A, Elliott E, Santos-Burgoa C, Schwartz L. 1993. Cancer epidemiology among styrene-butadiene rubber workers. IARC Sci Publ. (127):363–374. 8070882
Melnick RL, Huff J, Chou BJ, Miller RA. 1990. Carcinogenicity of 1,3-butadiene in C57BL/6 x C3H F_1_ mice at low exposure concentrations. Cancer Res. 50(20):6592–6599. 2208121
Melnick RL, Kohn MC. 1995. Mechanistic data indicate that 1,3-butadiene is a human carcinogen. J Carcinog. 16(2):157–163. 10.1093/carcin/16.2.157 7859343
Morrow NL. 1990. The industrial production and use of 1,3-butadiene. Environ Health Perspect. 86:7–8. 10.1289/ehp.90867 2205493
NIOSH. 1976. National Occupational Hazard Survey (1972-74). Cincinnati, OH: National Institute for Occupational Safety and Health. DHEW (NIOSH) Publication No. 78-114.
NIOSH. 1990. National Occupational Exposure Survey (1981-83). Cincinnati, OH: National Institute for Occupational Safety and Health. https://www.cdc.gov/noes/noes1/13410sic.html
NTP. 1984. Toxicology and Carcinogenesis Studies of 1,3-Butadiene (CAS No. 106-99-0) in B6C3F_1_ Mice (Inhalation Studies). Research Triangle Park, NC: National Toxicology Program. Technical Report Series no. 288. NIH Publication no. 84-2544.
Owen PE, Glaister JR, Gaunt IF, Pullinger DH. 1987. Inhalation toxicity studies with 1,3-butadiene. 3. Two year toxicity/carcinogenicity study in rats. Am Ind Hyg Assoc J 48(5):407-413. 10.1080/15298668791384959 10.1080/15298668791384959
Seaton MJ, Follansbee MH, Bond JA. 1995. Oxidation of 1,2-epoxy-3-butene to 1,2:3,4-diepoxybutane by cDNA-expressed human cytochromes P450 2E1 and 3A4 and human, mouse and rat liver microsomes. J Carcinog 16(10):2287-2293. 10.1093/carcin/16.10.2287 10.1093/carcin/16.10.2287
Shields PG, Xu GX, Blot WJ, Fraumeni JF Jr, Trivers GE, Pellizzari ED, Qu YH, Gao YT, Harris CC. 1995. Mutagens from heated Chinese and U.S. cooking oils. J Natl Cancer Inst 87(11):836-841. 10.1093/jnci/87.11.836 10.1093/jnci/87.11.836
SRI. 2009. Directory of Chemical Producers, Database ed. Menlo Park, CA: SRI Consulting.
TRI. 2009. TRI Explorer Chemical Report. Washington, DC: U.S. Environmental Protection Agency. https://www.epa.gov/triexplorer and select 1,3-Butadiene.
USITC. 2018. USITC Interactive Tariff and Trade DataWeb. Washington, DC: United States International Trade Commission. https://dataweb.usitc.gov/scripts/user_set.asp and search on HTS no. 2901241000.
Wallace LA. 1991. Comparison of risks from outdoor and indoor exposure to toxic chemicals. Environ Health Perspect 95:7-13. 10.1289/ehp.91957 10.1289/ehp.91957
Ward EM, Fajen JM, Ruder AM, Rinsky RA, Halperin WE, Fessler-Flesch CA. 1996. Mortality study of workers employed in 1,3-butadiene production units identified from a large chemical workers cohort. J Toxicol 113(1-3):157-168. 10.1016/0300-483X(96)03441-5 10.1016/0300-483X(96)03441-5