# 1-Bromopropane

CAS No. 106-94-5

Reasonably anticipated to be a human carcinogen

First listed in the Thirteenth Report on Carcinogens (2014)

Also known as n-propyl bromide

Figure 1

Chemical Structure of 1-Bromopropane

## Carcinogenicity

1-Bromopropane is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals. 1-Bromopropane, either directly or via reactive metabolites, causes molecular alterations that typically are associated with carcinogenesis, including genotoxicity, oxidative stress, and glutathione depletion. These alterations, observed mainly in vitro and in toxicity studies in rodents, are relevant to possible mechanisms of human carcinogenicity and support the relevance of the cancer studies in experimental animals to human carcinogenicity.

### Cancer Studies in Experimental Animals

Inhalation exposure to 1-bromopropane caused tumors in two rodent species and at several different tissue sites, including one tissue site in rats at which tumors are rare (NTP 2011).

In male rats, 1-bromopropane caused significant dose-related increases in the incidences of several types of benign and/or malignant skin tumors (keratoacanthoma; keratoacanthoma and squamous-cell carcinoma combined; and keratoacanthoma, squamous-cell carcinoma, basal-cell adenoma, and basal-cell carcinoma combined). Both female and male rats showed an increased incidence of large-intestine tumors (adenoma of the colon and rectum), which are rare tumors in rats. In females, the incidence was dose-related and statistically significantly higher than in concurrent controls, and it exceeded the historical control range for all routes of exposure used in studies, including inhalation exposure. In males, the incidence of large-intestine adenoma was not significantly increased but exceeded the historical control range for inhalation-exposure studies, and its occurrence was considered to be biologically significant because of the rarity of these tumors (which occurred in less than 0.2% of the historical controls). Although no carcinoma of the large intestine was observed in male or female rats in this study, adenoma of the large intestine has been shown to progress to carcinoma in other studies, and forms a morphologic continuum with carcinoma (Chang 1984; Deschner 1983; Nigro 1985).

In female mice, 1-bromopropane caused significant dose-related increases in the incidence of benign and malignant lung tumors combined (alveolar/bronchiolar adenoma and carcinoma).

These findings are supported by the observation of additional tumors in rats that may have been related to 1-bromopropane exposure, including malignant mesothelioma of the abdominal cavity and pancreatic islet tumors in males and skin tumors (squamous-cell papilloma, keratoacanthoma, and basal-cell adenoma or carcinoma) in females.

### Other Relevant Data

1-Bromopropane is well absorbed following ingestion, inhalation, or dermal exposure. Occupational exposure occurs primarily by inhalation and dermal contact. Unmetabolized 1-bromopropane has been detected in the urine of exposed workers at levels significantly correlated with exposure to 1-bromopropane in air (Ichihara et al. 2004; Kawai et al. 2001).

1-Bromopropane is metabolized via several pathways; 16 urinary metabolites have been detected in rodents, and several other metabolites have been proposed (Garner et al. 2006; Ishidao et al. 2002; Jones and Walsh 1979). The primary metabolic pathways in rodents are oxidation reactions catalyzed by cytochrome P450 (primarily CYP2E1) and glutathione conjugation. The available data on human metabolism of 1-bromopropane, although limited, suggest that some of its metabolic pathways in humans are similar to those observed in rodents. Four mercapturic conjugates identified in the urine of rodents were also identified in the urine of workers exposed to 1-bromopropane (Hanley et al. 2009). The major metabolite, N-acetyl-S-(n-propyl)-L-cysteine, has been detected in the urine of exposed workers at levels that increased with increasing levels of 1-bromopropane in ambient air (Hanley and Dunn 2006; Hanley et al. 2009; 2010; Valentine et al. 2007). This metabolite is produced in humans by conjugation of 1-bromopropane with glutathione, and that reaction also releases free bromide ions, another useful biomarker for human exposure to 1-bromopropane (Hanley et al. 2006; Jones and Walsh 1979). No studies were identified that tested for the occurrence in humans of the oxidative metabolites that are obligate intermediates to the measured conjugates.

### Studies on Mechanisms of Carcinogenesis

The mechanism(s) by which 1-bromopropane causes cancer is not known. However, exposure to 1-bromopropane has been shown to cause molecular alterations related to carcinogenicity, including genotoxicity (mutations and DNA damage), oxidative stress, glutathione depletion, and immunomodulation.

Studies have shown that 1-bromopropane can bind to macromolecules; it formed S-propylcysteine–globin adducts in exposed animals and humans (Valentine et al. 2007). Although 1-bromopropane did not induce mutations in bacteria under standard assay conditions, it did induce mutations in bacteria both with and without exogenous mammalian metabolic activation in the only reported study whose design was appropriate for testing a highly volatile chemical (Barber et al. 1981). It also caused mutations in cultured mammalian cells with or without mammalian metabolic activation (Elf Atochem 1996), as reviewed in NTP (2003) and DNA damage in cultured human cells without metabolic activation (Toraason et al. 2006). In addition, there is limited evidence of DNA damage in leukocytes from 1-bromopropane–exposed workers (Toraason et al. 2006). In rodents exposed in vivo, 1-bromopropane did not increase micronucleus formation in bone marrow (Kim et al. 1998), as reviewed in NTP (2003) or peripheral blood erythrocytes (Elf Atochem 1996), cited in NTP (2003; 2011) or cause dominant lethal mutations. However, the dominant lethal mutation assay is generally regarded as relatively insensitive for the detection of mutagenic agents (Saito-Suzuki et al. 1982; Yu et al. 2008).

There is evidence that metabolic activation plays a role in the genotoxicity and toxicity of 1-bromopropane. Several reactive metabolites (or intermediates) of 1-bromopropane have been identified in rodents, including glycidol and α-bromohydrin, and propylene oxide has been proposed as a metabolite (Garner et al. 2006). These compounds cause genotoxic effects in vitro, including DNA adduct formation, mutations, and DNA or chromosome damage (IARC 1994; 2000; Stolzenberg and Hine 1979). Glycidol and propylene oxide cause cytogenetic effects in vivo and are carcinogenic in experimental animals, and both substances are listed in the Report on Carcinogens as reasonably anticipated to be human carcinogens. These reactive and genotoxic metabolites may be responsible for at least some of the carcinogenic effects of 1-bromopropane. As with 1-bromopropane, oral exposure to glycidol caused rare tumors of the large intestine in rats, as did oral exposure to two halogenated alkane analogues of 1-bromopropane, tribromomethane and bromodichloromethane (NTP 1987; 1989; 1990).

Chronic exposure to 1-bromopropane may produce levels of oxidative metabolites that exceed the glutathione-conjugating capacity or may inhibit enzymes required for glutathione synthesis. Because glutathione is an important cellular defense mechanism, reduced levels can lead to oxidative stress, increased toxicity, and carcinogenicity. Numerous studies have shown that 1-bromopropane induces both oxidative stress and glutathione depletion (Huang et al. 2011; Lee et al. 2005; Lee et al. 2007; Lee et al. 2010a; Liu et al. 2009; Liu et al. 2010). Studies with Cyp2e1^/^ knockout mice, cytochrome P450 inhibitors, or a glutathione synthesis inhibitor showed that this metabolic activation pathway is involved in 1-bromopropane–induced toxicity, including neurological and reproductive effects, hepatotoxicity, and immunosuppression (Lee et al. 2007; Lee et al. 2010a; Lee et al. 2010b; NTP 2003; 2011). Neurological effects of 1-bromopropane exposure have also been reported in humans (Ichihara et al. 2012; Li et al. 2010).

It is unclear whether induction of immunotoxicity by 1-bromopropane plays a role in tumor development. Recent studies have shown that 1-bromopropane causes immunosuppression in rodents (Anderson et al. 2010; Lee et al. 2007). In particular, it reduced the numbers of T cells and T-cell subpopulations. In addition, there is evidence that 1-bromopropane causes an inflammatory response. It induced dose-related increases in gene expression and production of proinflammatory cytokines in mouse macrophages (Han et al. 2008) and an inflammatory response in rats (NTP 2011). However, chronic respiratory inflammation and lung tumors were not associated in rodents; respiratory inflammation occurred in rats but not mice, whereas lung tumors occurred in mice but not rats.

### Cancer Studies in Humans

No epidemiological studies or case reports were identified that evaluated the relationship between human cancer and exposure specifically to 1-bromopropane.

## Properties

1-Bromopropane is a halogenated alkane that exists at room temperature as a colorless to pale-yellow, volatile liquid with a strong, characteristic odor (NTP 2011). It is slightly soluble in water and in most organic solvents, including acetone, ethanol, ether, benzene, chloroform, and carbon tetrachloride. It is less flammable than many other halogenated alkanes at room temperature. Thermal decomposition of 1-bromopropane produces hydrogen bromide. 1-Bromopropane can react with oxidizing agents to form hazardous flammable compounds and with water to produce acids. Physical and chemical properties of 1-bromopropane are listed in Table 1.

Table 1 Properties of 1-Bromopropane

Property | Information
Molecular weight | 123.0^a^
Specific gravity | 1.353 at 20°C/20°C^b^
Melting point | −110°C^a^
Boiling point | 64.7°C^a^
Log K_ow_ | 2.10^b^
Water solubility | 2.45 g/L at 20°C^b^
Vapor pressure | 110.8 mm Hg at 20°C^a^
Vapor density relative to air | 4.25^b^

Sources: ^a^NTP (2003). ^b^HSDB (2006).

## Use

1-Bromopropane is used primarily as a solvent cleaner in vapor and immersion degreasing operations to clean optics, electronics, and metals and as a solvent vehicle in industries using aerosol-applied adhesives, such as foam cushion manufacturing. However, its use as an aerosol solvent or adhesive could be affected by the proposed U.S. Environmental Protection Agency (EPA) rule that finds 1-bromopropane to be unacceptable for these uses (see Regulations). In recent years, 1-bromopropane usage has increased as a result of new industrial and commercial uses as a substitute for ozone-depleting chemicals or suspected carcinogens (e.g., as an alternative to tetrachloroethylene in the dry-cleaning industry) (Blando et al. 2010). 1-Bromopropane also has potential for use as a spot remover in the textile industry; however, an evaluation of 1-bromopropane as a substitute for trichloroethylene concluded that chronic toxicity data were insufficient, and use of 1-bromopropane was not recommended until more data were available (Mirza et al. 2000). In the past, 1-bromopropane was used primarily as a solvent for fats, waxes, and resins and as an intermediate in the synthesis of pharmaceuticals, insecticides, quaternary ammonium compounds, flavors, and fragrances in generally well-controlled, closed processes (Hanley et al. 2006; NTP 2003).

## Production

1-Bromopropane is a high-production-volume chemical. In 2012, 1-bromopropane was manufactured by at least 21 companies worldwide, including at least one company in the United States (SRI 2012). Combined U.S. production and imports of 1-bromopropane have increased greatly since the early 1980s (as shown in Table 2) and in 2015 were reported by EPA to be in the range of 10 to 50 million pounds (EPA 2016). No import or export data specifically for 1-bromopropane were identified.

Table 2 Production, Imports, and Exports of 1-Bromopropane

Category | Year | Quantity (lb)
Production + imports | 2015^a^ 1998–2006^b^ 1994^b^ 1986, 1990^b^ | 10 to 50 million 1 million to <10 million >500,000 to 1 million 10,000 to 500,000

Sources: ^a^EPA (2016). ^b^EPA (2014).

## Exposure

A significant number of people in the United States are exposed to 1-bromopropane as a result of widespread usage, high production volume, and high levels of 1-bromopropane in commercial and industrial settings.

Occupational exposure to 1-bromopropane may occur through inhalation or dermal contact at workplaces where 1-bromopropane is produced or used (HSDB 2006). Concentrations of 1-bromopropane in air (8- to 12-hour time-weighted averages [TWAs]) from all studies identified across several U.S. industrial sectors ranged from not detected to 380 ppm, with the highest concentrations being for adhesive use and the lowest for vapor degreasing (Figure 2). Sprayers in the adhesive industry had the highest exposure, which ranged from 18 to 380 ppm across several studies. Exposure data for 1-bromopropane manufacturing were not available for the United States. Manufacturing exposure reported from China (Ichihara et al. 2004) ranged from not detectable to 170.5 ppm for processes that included adding materials to large reaction pots. However, production methods reported in a patent application by a U.S. manufacturer included numerous control processes to contain 1-bromopropane, which would likely reduce potential exposure substantially. The graph on the next page shows TWA 1-bromopropane exposure levels from representative studies of adhesive application (Hanley et al. 2006), manufacturing in China (Ichihara et al. 2004), dry-cleaning (Eisenberg and Ramsey 2010), aerosol solvent use (Graul 2012), vapor degreasing (Hanley et al. 2010), and cleaning and painting in workshops using 1-bromopropane solvents (Kawai et al. 2001).

Figure 2

Occupational Exposure to 1-Bromopropane, by Industry

Time-weighted-average 1-bromopropane exposure levels as geometric means (adhesives, vapor degreasing, and other); arithmetic mean (dry cleaning); or not reported (manufacturing and aerosol solvents). The dashed vertical line represents the American Conference of Governmental Industrial Hygienists threshold limit value – time-weighted average (TLV-TWA) of 10 ppm.

Among workers at polyurethane foam furniture cushion manufacturing facilities, geometric mean values for daily urinary bromide excretion and urinary N-acetyl-S-propylcysteine concentrations were approximately 4 times as high for adhesive sprayers as for non-sprayers (Hanley et al. 2006; Hanley et al. 2009). Concentrations of 1-bromopropane in exhaled breath also were consistently higher among sprayers than among workers performing other jobs. A National Institute for Occupational Safety and Health (NIOSH) Health Hazard Evaluation (HHE) of a furniture foam cushion manufacturing facility found the average difference between end-of-week and start-of-week serum bromide concentrations to be 23 mg/L for exposed workers, compared with 3 mg/L for unexposed workers (Harney et al. 2003). NIOSH HHEs and follow-ups at two facilities showed that 1-bromopropane air concentrations (TWAs) could be reduced by 80% or more through implementation of NIOSH recommendations for engineering controls, such as ventilation improvements and enclosure of spray tables (Reh et al. 2002).

The general population may be exposed to 1-bromopropane through inhalation of ambient air in the vicinity of industrial facilities where 1-bromopropane is used as an adhesive. EPA used air dispersion modeling to estimate 1-bromopropane concentrations in ambient air at a distance of 100 m from model facilities. The estimated concentrations were 0.138 mg/m^3^ [0.0274 ppm] for facilities with average adhesive use and 1.38 mg/m^3^ [0.274 ppm] for facilities with high adhesive use (Morris and Wolf 2003). EPA also estimated daily inhalation uptake of 1-bromopropane for a person living 100 m from a model facility to be 0.0537 mg/kg for average-adhesive-use facilities and 0.537 mg/kg for high-adhesive-use facilities.

Based on its production levels and industrial uses, 1-bromopropane may be released to the environment through various waste streams. 1-Bromopropane has been detected in temperate marine macroalgal tissue and is believed to be transported from these algae to the marine environment (HSDB 2006). No data were found on levels of 1-bromopropane in ambient air, drinking water, surface water, soil, food, or consumer products or on non-occupational exposure to 1-bromopropane.

## Regulations

### California Occupational Safety and Health Standards Board (OSHSB)

Permissible exposure limit (PEL) = 5 ppm.

Potential for dermal absorption.

### Department of Transportation (DOT)

Bromopropanes are considered hazardous materials, and special requirements have been set for marking, labeling, and transporting these materials.

### Environmental Protection Agency (EPA)

#### Emergency Planning and Community Right-to-Know Act

Toxics Release Inventory: Listed substance subject to reporting requirements.

#### Significant New Alternatives Policy (SNAP) Program

The EPA SNAP program reviews alternatives to ozone-depleting substances and approves the use of alternatives that do not present substantially greater risk to the public health and environment than the substance they replace or other available substitutes. The EPA SNAP program has made the following determinations regarding various end uses of 1-bromopropane:

- Solvent in industrial equipment for metals cleaning, electronics cleaning, or precision cleaning as a substitute for CFC-113 and methyl chloroform: acceptable (final rule).
- Coatings as a substitute for CFC-113, HCFC-141b, and methyl chloroform: acceptable subject to the condition that use is limited to coatings facilities that have provided EPA data which demonstrate their ability to maintain acceptable workplace exposures (proposed rule).
- Aerosol solvents as a substitute for CFC-113, HCFC-141b, and methyl chloroform: unacceptable (proposed rule).
- Adhesives as a substitute for CFC-113, HCFC-141b, and methyl chloroform: unacceptable (proposed rule).

## Guidelines

### American Conference of Governmental Industrial Hygienists (ACGIH)

Threshold limit value – time-weighted average (TLV-TWA) = 0.1 ppm.

## References

Anderson SE, Munson AE, Butterworth LF, Germolec D, Morgan DL, Roycroft JA, Dill J, Meade BJ. 2010. Whole-body inhalation exposure to 1-bromopropane suppresses the IgM response to sheep red blood cells in female B6C3F_1_ mice and Fisher 344/N rats. Inhal Toxicol 22(2):125-132. 10.3109/08958370902953910 10.3109/08958370902953910
Barber ED, Donish WH, Mueller KR. 1981. A procedure for the quantitative measurement of the mutagenicity of volatile liquids in the Ames Salmonella/microsome assay. Mutat Res. 90(1):31–48. 10.1016/0165-1218(81)90048-3 7029269
Blando JD, Schill DP, De La Cruz MP, Zhang L, Zhang J. 2010. Preliminary study of propyl bromide exposure among New Jersey dry cleaners as a result of a pending ban on perchloroethylene. J Air Waste Manag Assoc 60(9):1049-1056. 10.3155/1047-3289.60.9.1049 10.3155/1047-3289.60.9.1049
Chang WW. 1984. Histogenesis of colon cancer in experimental animals. Scand J Gastroenterol Suppl. 104:27–43. 6396831
Deschner EE. 1983. Adenomas: Preneoplastic events, growth and development in man and experimental systems. Pathol Annu. 18(Pt 1):205–219. 6348673
Eisenberg J, Ramsey J. 2010. Evaluation of 1-Bromopropane Use in Four New Jersey Commercial Dry Cleaning Facilities. Washington, DC: National Institute for Occupational Safety and Health. Health Hazard Evaluation HETA Report No. 2008-0175-3111.
Elf Atochem. 1996. In Vitro Mammalian Cell Gene Mutation Test in L5178Y TK+/- Mouse Lymphoma Cells of n-Propyl Bromide. Miserey, France: Centre International de Toxicologie. Study No. 13293.
EPA. 2014. Non-confidential 2012 Chemical Data Reporting (CDR) Database. Washington, DC: U.S. Environmental Protection Agency; https://java.epa.gov/oppt_chemical_search and select CDR and search on CAS no.
EPA. 2016. Chemical Data Reporting Summary: 1-Bromopropane. Washington, DC: U.S. Environmental Protection Agency. https://chemview.epa.gov/chemview and search on CAS number or substance name and select Manufacturing, Processing, Use, and Release Data Maintained by EPA and select Chemical Data Reporting Details.
Garner CE, Sumner SC, Davis JG, Burgess JP, Yueh Y, Demeter J, Zhan Q, Valentine J, Jeffcoat AR, Burka LT, et al. 2006. Metabolism and disposition of 1-bromopropane in rats and mice following inhalation or intravenous administration. Toxicol Appl Pharmacol 215(1):23-36. 10.1016/j.taap.2006.01.010 10.1016/j.taap.2006.01.010
Graul F. 2012. Summary of Data on Workplace Exposure to n-Propyl Bromide: Public Comment Submitted February 28, 2012 by F. Graul, HSIA Executive Director to R. Lunn at NTP, Research Triangle Park, NC. Arlington, VA: Halogenated Solvents Industry Alliance. https://ntp.niehs.nih.gov/go/37663.
Han EH, Hwang YP, Lee KJ, Jeong TC, Jeong HG. 2008. 1-Bromopropane induces macrophage activation via extracellular signal-regulated kinase 1/2 MAPK and NF-ϰB pathways. Cancer Lett 262(1):28-36. 10.1016/j.canlet.2007.11.024 10.1016/j.canlet.2007.11.024
Hanley KW, Dunn K. 2006. Workers’ Exposures to n-Propyl Bromide at a Helicopter Transmission Factory. Cincinnati, OH: National Institute for Occupational Safety and Health. Report No. IWSB 232.11.
Hanley KW, Dunn K, Sollberger R. 2006. Workers’ Exposures to n-Propyl Bromide at an Aerospace Components Manufacturer. Cincinnati, OH: National Institute for Occupational Safety and Health. Report No. IWSB 232.12.
Hanley KW, Petersen MR, Cheever KL, Luo L. 2009. N-acetyl-S-(n-propyl)-L-cysteine in urine from workers exposed to 1-bromopropane in foam cushion spray adhesives. Ann Occup Hyg 53(7):759-769. 10.1093/annhyg/mep051 10.1093/annhyg/mep051
Hanley KW, Petersen MR, Cheever KL, Luo L. 2010. Bromide and N-acetyl-S-(n-propyl)-L-cysteine in urine from workers exposed to 1-bromopropane solvents from vapor degreasing or adhesive manufacturing. Int Arch Occup Environ Health 83(5):571-584. 10.1007/s00420-010-0524-4 10.1007/s00420-010-0524-4
Harney JM, Nemhauser JB, Reh CM, Trout D. 2003. NIOSH Health Hazard Evaluation Report for Marx Industries, Inc., Sawmills, North Carolina. Cincinnati, OH: National Institute for Occupational Safety and Health. Report No. HETA 99-0260-2906. https://www.cdc.gov/niosh/hhe/reports/pdfs/1999-0260-2906.pdf
HSDB. 2006. Hazardous Substances Data Bank. Bethesda, MD: National Library of Medicine. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
Huang Z, Ichihara S, Oikawa S, Chang J, Zhang L, Takahashi M, Subramanian K, Mohideen SS, Wang Y, Ichihara G. 2011. Proteomic analysis of hippocampal proteins of F344 rats exposed to 1-bromopropane. Toxicol Appl Pharmacol 257(1):93-101. 10.1016/j.taap.2011.08.023 10.1016/j.taap.2011.08.023
IARC. 1994. Some Industrial Chemicals. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Vol. 60. Lyon, France: International Agency for Research on Cancer; Propylene oxide; p. 181–213.
IARC. 2000. Some Industrial Chemicals. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Vol. 77. Lyon, France: International Agency for Research on Cancer; Glycidol; p. 469–486.
Ichihara G, Kitoh J, Li W, Ding X, Ichihara S, Takeuchi Y. 2012. Neurotoxicity of 1-bromopropane: Evidence from animal experiments and human studies. J Adv Res. 3(2):91–98. 10.1016/j.jare.2011.04.005
Ichihara G, Li W, Ding X, Peng S, Yu X, Shibata E, Yamada T, Wang H, Itohara S, Kanno S, et al. 2004. A survey on exposure level, health status, and biomarkers in workers exposed to 1-bromopropane. Am J Ind Med 45(1):63-75. 10.1002/ajim.10320 10.1002/ajim.10320
Ishidao T, Kunugita N, Fueta Y, Arashidani K, Hori H. 2002. Effects of inhaled 1-bromopropane vapor on rat metabolism. Toxicol Lett. 134(1-3):237–243. 10.1016/S0378-4274(02)00171-6 12191883
Jones AR, Walsh DA. 1979. The oxidative metabolism of 1-bromopropane in the rat. Xenobiotica 9(12):763-772. 10.3109/00498257909042344 10.3109/00498257909042344
Kawai T, Takeuchi A, Miyama Y, Sakamto K, Zhang ZW, Higashikawa K, Ikeda M. 2001. Biological monitoring of occupational exposure to 1-bromopropane by means of urinalysis for 1-bromopropane and bromide ion. Biomarkers 6(5):303-312. 10.1080/13547500110034817 10.1080/13547500110034817
Kim H, Chung J, Chung Y, Kim K, Maeng S, Hang C, et al. 1998. Toxicological Studies on Inhalation of 1-Bromopropane Using Rats: Technical Report Submitted to the Industrial Health Research Institute. Yongsan Gu, Republic of Korea: Korea Industrial Safety Corporation.
Lee SK, Jeon TW, Kim YB, Lee ES, Jeong HG, Jeong TC. 2007. Role of glutathione conjugation in the hepatotoxicity and immunotoxicity induced by 1-bromopropane in female BALB/c mice. J Appl Toxicol 27(4):358-367. 10.1002/jat.1214 10.1002/jat.1214
Lee SK, Jo SW, Jeon TW, Jun IH, Jin CH, Kim GH, Lee DJ, Kim TO, Lee ES, Jeong TC. 2005. Hepatotoxic effect of 1-bromopropane and its conjugation with glutathione in male ICR mice. Arch Pharm Res 28(10):1177-1182. 10.1007/BF02972983 10.1007/BF02972983
Lee SK, Kang MJ, Jeon TW, Ha HW, Yoo JW, Ko GS, Kang W, Jeong HG, Lyoo WS, Jeong TC. 2010a. Role of metabolism in 1-bromopropane-induced hepatotoxicity in mice. J Toxicol Environ Health A 73(21-22):1431-1440. 10.1080/15287394.2010.511546 10.1080/15287394.2010.511546
Lee SK, Lee DJ, Ko GS, Yoo SH, Ha HW, Kang MJ, Jeong TC. 2010b. Role of glutathione conjugation in 1-bromobutane-induced hepatotoxicity in mice. Food Chem Toxicol 48(10):2707-2711. 10.1016/j.fct.2010.06.044 10.1016/j.fct.2010.06.044
Li W, Shibata E, Zhou Z, Ichihara S, Wang H, Wang Q, Li J, Zhang L, Wakai K, Takeuchi Y, et al. 2010. Dose-dependent neurologic abnormalities in workers exposed to 1-bromopropane. J Occup Environ Med 52(8):769-777. 10.1097/JOM.0b013e3181eaded7 10.1097/JOM.0b013e3181eaded7
Liu F, Ichihara S, Mohideen SS, Sai U, Kitoh J, Ichihara G. 2009. Comparative study on susceptibility to 1-bromopropane in three mice strains. Toxicol Sci 112(1):100-110. 10.1093/toxsci/kfp173 10.1093/toxsci/kfp173
Liu F, Ichihara S, Valentine WM, Itoh K, Yamamoto M, Sheik Mohideen S, Kitoh J, Ichihara G. 2010. Increased susceptibility of Nrf2-null mice to 1-bromopropane-induced hepatotoxicity. Toxicol Sci 115(2):596-606. 10.1093/toxsci/kfq075 10.1093/toxsci/kfq075
Mirza T, Gérin M, Bégin D, Drolet D. 2000. A study on the substitution of trichloroethylene as a spot remover in the textile industry. Am Ind Hyg Assoc J 61(3):431-438. 10.1080/15298660008984555 10.1080/15298660008984555
Morris M, Wolf K. 2003. Alternative Adhesive Technologies in the Foam Furniture and Bedding Industries. Los Angeles, CA: Institute for Research and Technical Assistance. Prepared for the U.S. Environmental Protection Agency.
Nigro ND. 1985. Animal model for colorectal cancer. Prog Clin Biol Res. 186:161–173. 4034597
NTP. 1987. Toxicology and Carcinogenesis Studies of Bromodichloromethane (CAS No. 75-27-4) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Research Triangle Park, NC: National Toxicology Program. NTP Technical Report Series No. 321.
NTP. 1989. Toxicology and Carcinogenesis Studies of Tribromomethane (Bromoform) (CAS No. 75-25-2) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Research Triangle Park, NC: National Toxicology Program. NTP Technical Report Series No. 350.
NTP. 1990. Toxicology and Carcinogenesis Studies of Glycidol (CAS No. 556-52-5) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Research Triangle Park, NC: National Toxicology Program. NTP Technical Report Series No. 374.
NTP. 2003. NTP-CERHR Monograph on the Potential Human Reproductive and Developmental Effects of 1-Bromopropane. Research Triangle Park, NC: National Toxicology Program, Center for the Evaluation of Risks to Human Reproduction.
NTP. 2011. NTP Technical Report on the Toxicology and Carcinogenesis Studies of 1 Bromopropane (CAS No. 106-94-5) in F344/N Rats and B6C3F_1_ Mice (Inhalation Studies). Research Triangle Park, NC: National Toxicology Program. NTP TR 564, NIH Publication No. 11-5906.
Reh CM, Mortimer V, Nemhauser JB, Trout D. 2002. NIOSH Health Hazard Evaluation Report. Custom Products, Inc., Mooresville, North Carolina. NIOSH Health Hazard Evaluation Report. Cincinnati, OH: National Institute for Occupational Safety and Health. HHE Report no. HETA 98-0153-2883.
Saito-Suzuki R, Teramoto S, Shirasu Y. 1982. Dominant lethal studies in rats with 1,2-dibromo-3-chloropropane and its structurally related compounds. Mutat Res 101(4):321-327. 10.1016/0165-1218(82)90125-2 10.1016/0165-1218(82)90125-2
SRI. 2012. Directory of Chemical Producers, Database ed. Menlo Park, CA: SRI Consulting.
Stolzenberg SJ, Hine CH. 1979. Mutagenicity of halogenated and oxygenated three-carbon compounds. J Toxicol Environ Health 5(6):1149-1158. 10.1080/15287397909529820 10.1080/15287397909529820
Toraason M, Lynch DW, DeBord DG, Singh N, Krieg E, Butler MA, Toennis CA, Nemhauser JB. 2006. DNA damage in leukocytes of workers occupationally exposed to 1-bromopropane. Mutat Res 603(1):1-14. 10.1016/j.mrgentox.2005.08.015 10.1016/j.mrgentox.2005.08.015
Valentine H, Amarnath K, Amarnath V, Li W, Ding X, Valentine WM, Ichihara G. 2007. Globin s-propyl cysteine and urinary N-acetyl-S-propylcysteine as internal biomarkers of 1-bromopropane exposure. Toxicol Sci 98(2):427-435. 10.1093/toxsci/kfm126 10.1093/toxsci/kfm126
Yu WJ, Kim JC, Chung MK. 2008. Lack of dominant lethality in mice following 1-bromopropane treatment. Mutat Res 652(1):81-87. 10.1016/j.mrgentox.2008.01.001 10.1016/j.mrgentox.2008.01.001