# Appendix G Listed Substances by CAS Number

Appendix G is a list of Chemical Abstracts Service Registry Numbers (CAS numbers) of listed substances for which a CAS number is available. For listings of structurally related chemicals, the list of CAS numbers is not comprehensive for all the chemicals belonging to the class; it generally includes the CAS number of the major chemicals or metals that are highlighted in the profile.

50-00-0 see Formaldehyde

50-18-0 see Cyclophosphamide

50-28-2 (estradiol-17β) see Estrogens, Steroidal

50-29-3 see Dichlorodiphenyltrichloroethane

50-32-8 (benzo[a]pyrene) see Polycyclic Aromatic Hydrocarbons: 15 Listings

50-55-5 see Reserpine

51-52-5 see Propylthiouracil

51-79-6 see Urethane

52-24-4 see Thiotepa

53-16-7 (estrone) see Estrogens, Steroidal

53-70-3 (dibenz[a,h]anthracene) see Polycyclic Aromatic Hydrocarbons: 15 Listings

53-96-3 see 2-Acetylaminoﬂuorene

55-18-5 (N-Nitrosodiethylamine) see N-Nitrosamines: 15 Listings

55-86-7 see Nitrogen Mustard Hydrochloride

55-98-1 see 1,4-Butanediol Dimethanesulfonate

56-23-5 see Carbon Tetrachloride

56-53-1 see Diethylstilbestrol

56-55-3 (benz[a]anthracene) see Polycyclic Aromatic Hydrocarbons: 15 Listings

56-75-7 see Chloramphenicol

57-14-7 see 1,1-Dimethylhydrazine

57-41-0 (phenytoin) see Phenytoin and Phenytoin Sodium

57-57-8 see β-Propiolactone

57-63-6 (ethinylestradiol) see Estrogens, Steroidal

57-83-0 see Progesterone

58-89-9 (lindane) see Lindane, Hexachlorocyclohexane (Technical Grade), and Other Hexachlorocyclohexane Isomers

59-89-2 (N-nitrosomorpholine) see N-Nitrosamines: 15 Listings

60-11-7 see 4-Dimethylaminoazobenzene

61-82-5 see Amitrole

62-44-2 (phenacetin) see Phenacetin and Analgesic Mixtures Containing Phenacetin

62-50-0 see Ethylmethanesulfonate

62-55-5 see Thioacetamide

62-56-6 see Thiourea

62-75-9 (N-nitrosodimethylamine) see N-Nitrosamines: 15 Listings

63-92-3 see Phenoxybenzamine Hydrochloride

64-67-5 see Diethyl Sulfate

66-27-3 see Methyl Methanesulfonate

67-66-3 see Chloroform

67-72-1 see Hexachloroethane

68-22-4 see Norethisterone

70-25-7 (N-methyl-N′-nitro-N-nitrosoguanidine) see N-Nitrosamines: 15 Listings

71-43-2 see Benzene

71-48-7 (cobalt acetate) see Cobalt-Related Exposures

72-33-3 (mestranol) see Estrogens, Steroidal

75-01-4 (vinyl chloride) see Vinyl Halides (Selected)

75-02-5 (vinyl fluoride) see Vinyl Halides (Selected)

75-07-0 see Acetaldehyde

75-09-2 see Dichloromethane

75-21-8 see Ethylene Oxide

75-27-4 see Bromodichloromethane

75-52-5 see Nitromethane

75-55-8 see 2-Methylaziridine

75-56-9 see Propylene Oxide

75-96-7 (tribromoacetic acid) see Haloacetic Acids Found as Water Disinfection By-Products (Selected)

77-09-8 see Phenolphthalein

77-78-1 see Dimethyl Sulfate

78-00-2 (tetraethyl lead) see Lead and Lead Compounds

78-79-5 see Isoprene

79-01-6 see Trichloroethylene

79-06-1 see Acrylamide

79-43-6 (dichloroacetic acid) see Selected Haloacetic Acids Found as Water Disinfection By-Products

79-44-7 see Dimethylcarbamoyl Chloride

79-46-9 see 2-Nitropropane

81-49-2 see 1-Amino-2,4-dibromoanthraquinone

82-28-0 see 1-Amino-2-methylanthraquinone

87-86-5 (pentachlorophenol) see Pentachlorophenol and By-products of Its Synthesis

88-06-2 see 2,4,6-Trichlorophenol

88-72-2 see o-Nitrotoluene

90-04-0 (o-anisidine) see o-Anisidine and Its Hydrochloride

90-94-8 see Michler’s Ketone

91-08-7 (2,6-toluene diisocyanate) see Toluene Diisocyanates

91-20-3 see Naphthalene

91-23-6 see o-Nitroanisole

91-59-8 see 2-Naphthylamine

91-94-1 (3,3′-dichlorobenzidine) see 3,3′-Dichlorobenzidine and Its Dihydrochloride

92-67-1 see 4-Aminobiphenyl

92-87-5 (benzidine) see Benzidine and Dyes Metabolized to Benzidine

93-15-2 see Methyleugenol

94-59-7 see Safrole

95-06-7 see Sulfallate

95-53-4 (o-toluidine) see o-Toluidine and Its Hydrochloride

95-69-2 (p-chloro-o-toluidine) see p-Chloro-o-toluidine and Its Hydrochloride

95-80-7 see 2,4-Diaminotoluene

95-83-0 see 4-Chloro-o-phenylenediamine

96-09-3 see Styrene-7,8-oxide

96-12-8 see 1,2-Dibromo-3-chloropropane

96-13-9 see 2,3-Dibromo-1-propanol

96-18-4 see 1,2,3-Trichloropropane

96-45-7 see Ethylene Thiourea

97-56-3 see o-Aminoazotoluene

98-07-7 see Benzotrichloride

98-82-8 see Cumene

98-95-3 see Nitrobenzene

100-42-5 see Styrene

100-75-4 (N-nitrosopiperidine) see N-Nitrosamines: 15 Listings

101-14-4 see 4,4′-Methylenebis(2-chloroaniline)

101-61-1 see 4,4′-Methylenebis(N,N-dimethyl)benzeneamine

101-77-9 (4,4′-methylenedianiline) see 4,4′-Methylenedianiline and its Dihydrochloride

101-80-4 see 4,4′-Oxydianiline

101-90-6 see Diglycidyl Resorcinol Ether

106-46-7 see 1,4-Dichlorobenzene

106-87-6 see 4-Vinyl-1-cyclohexene Diepoxide

106-89-8 see Epichlorohydrin

106-93-4 see 1,2-Dibromoethane

106-94-5 see 1-Bromopropane

106-99-0 see 1,3-Butadiene

107-06-2 see 1,2-Dichloroethane

107-13-1 see Acrylonitrile

107-30-2 (chloromethyl methyl ether) see Bis(chloromethyl) Ether and Technical-Grade Chloromethyl Methyl Ether

110-00-9 see Furan

115-28-6 see Chlorendic Acid

116-14-3 see Tetraﬂuoroethylene

117-10-2 see Danthron

117-79-3 see 2-Aminoanthraquinone

117-81-7 see Di(2-ethylhexyl) Phthalate

118-74-1 see Hexachlorobenzene

119-90-4 (3,3′-dimethoxybenzidine) see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine

119-93-7 (3,3′-dimethylbenzidine) see 3,3′-Dimethylbenzidine and Dyes Metabolized to 3,3′-Dimethylbenzidine

120-71-8 see p-Cresidine

122-66-7 see Hydrazobenzene

123-91-1 see 1,4-Dioxane

126-72-7 see Tris(2,3-dibromopropyl) Phosphate

126-99-8 see Chloroprene

127-18-4 see Tetrachloroethylene

131-52-2 (pentachlorophenol, sodium salt) see Pentachlorophenol and By-products of Its Synthesis

134-29-2 (o-anisidine hydrochloride) see o-Anisidine and Its Hydrochloride

135-20-6 see Cupferron

136-35-6 see Diazoaminobenzene

136-40-3 see Phenazopyridine Hydrochloride

139-13-9 see Nitrilotriacetic Acid

139-65-1 see 4,4′-Thiodianiline

143-50-0 see Kepone

148-82-3 see Melphalan

154-93-8 bis(chloroethyl) nitrosourea see Nitrosourea Chemotherapeutic Agents

189-55-9 (dibenzo[a,i]pyrene) see Polycyclic Aromatic Hydrocarbons: 15 Listings

189-64-0 (dibenzo[a,h]pyrene) see Polycyclic Aromatic Hydrocarbons: 15 Listings

191-30-0 (dibenzo[a,l]pyrene) see Polycyclic Aromatic Hydrocarbons: 15 Listings

192-65-4 (dibenzo[a,e]pyrene) see Polycyclic Aromatic Hydrocarbons: 15 Listings

193-39-5 (indeno[1,2,3-cd]pyrene) see Polycyclic Aromatic Hydrocarbons: 15 Listings

194-59-2 (7H-dibenzo[c,g]carbazole) see Polycyclic Aromatic Hydrocarbons: 15 Listings

205-82-3 (benzo[j]ﬂuoranthrene) see Polycyclic Aromatic Hydrocarbons: 15 Listings

205-99-2 (benzo[b]ﬂuoranthrene) see Polycyclic Aromatic Hydrocarbons: 15 Listings

207-08-9 (benzo[k]ﬂuoranthrene) see Polycyclic Aromatic Hydrocarbons: 15 Listings

224-42-0 (dibenz[a,j]acridine) see Polycyclic Aromatic Hydrocarbons: 15 Listings

226-36-8 (dibenz[a,h]acridine) see Polycyclic Aromatic Hydrocarbons: 15 Listings

298-81-7 (methoxsalen) see Methoxsalen with Ultraviolet A Therapy

302-01-2 (hydrazine) see Hydrazine and Hydrazine Sulfate

303-47-9 see Ochratoxin A

305-03-3 see Chlorambucil

313-67-7 (aristolochic acid I) see Aristolochic Acids

319-84-6 (𝛼-hexachlorocyclohexane) see Lindane, Hexachlorocyclohexane (Technical Grade), and Other Hexachlorocyclohexane Isomers

319-85-7 (β-hexachlorocyclohexane) see Lindane, Hexachlorocyclohexane (Technical Grade), and Other Hexachlorocyclohexane Isomers

320-67-2 see Azacitidine

366-70-1 (procarbazine hydrochloride) see Procarbazine and Its Hydrochloride

373-02-4 (nickel acetate) see Nickel and Nickel Compounds

434-07-1 see Oxymetholone

443-48-1 see Metronidazole

446-86-6 see Azathioprine

475-80-9 (aristolochic acid II) see Aristolochic Acids

505-60-2 see Mustard Gas

509-14-8 see Tetranitromethane

513-37-1 see Dimethylvinyl Chloride

542-75-6 (1,3-dichloropropene) see 1,3-Dichloropropene (Technical Grade)

542-88-1 (bis(chloromethyl) ether) see Bis(chloromethyl) Ether and Technical-Grade Chloromethyl Methyl Ether

556-52-5 see Glycidol

563-47-3 see 3-Chloro-2-methylpropene

569-61-9 see Basic Red 9 Monohydride

584-84-9 (2,4-toluene diisocyanate) see Toluene Diisocyanates

593-60-2 (vinyl bromide) see Vinyl Halides (Selected)

612-82-8 (3,3′-dimethylbenzidine dihydrochloride) see 3,3′-Dimethybenzidine and Dyes Metabolized to 3,3′-Dimethylbenzidine

612-83-9 (3,3′-dichlorobenzidine dihydrochloride) see 3,3′-Dichlorobenzidine and Its Dihydrochloride

621-64-7 (N-nitrosodi-n-propylamine) see N-Nitrosamines: 15 Listings

630-93-3 (phenytoin sodium) see Phenytoin and Phenytoin Sodium

631-64-1 (dibromoacetic acid) see Haloacetic Acids Found as Water Disinfection By-Products (Selected)

671-16-19 (procarbazine) see Procarbazine and Its Hydrochloride

680-31-9 see Hexamethylphosphoramide

684-93-5 (N-nitroso-N-methylurea) see N-Nitrosamines: 15 Listings

759-73-9 (N-nitroso-N-ethylurea) see N-Nitrosamines: 15 Listings

924-16-3 (N-nitrosodi-n-butylamine) see N-Nitrosamines: 15 Listings

930-55-2 (N-nitrosopyrrolidine) see N-Nitrosamines: 15 Listings

1116-54-7 (N-nitrosodiethanolamine) see N-Nitrosamines: 15 Listings

1120-71-4 see 1,3-Propane Sultone

1304-56-9 (beryllium oxide) see Beryllium and Beryllium Compounds

1307-96-6 (cobalt oxide) see Cobalt-Related Exposures

1309-64-4 see Antimony Trioxide

1313-99-1 (nickel monoxide) see Nickel and Nickel Compounds

1314-20-1 (thorium dioxide) see Ionizing Radiation

1327-53-3 (arsenic trioxide) see Arsenic and Inorganic Arsenic Compounds

1332-21-4 see Asbestos

1333-82-0 (chromium trioxide) see Chromium Hexavalent Compounds

1335-32-6 (lead subacetate) see Lead and Lead Compounds

1336-36-3 see Polychlorinated Biphenyls

1402-68-2 see Aﬂatoxins

1464-53-5 see Diepoxybutane

1746-01-6 see 2,3,7,8-Tetrachlorodibenzo-p-dioxin

1836-75-5 see Nitrofen

1937-37-7 (C.I. direct black 38) see Benzidine and Dyes Metabolized to Benzidine

2385-85-5 see Mirex

2425-06-1 see Captafol

2429-74-5 (C.I. direct blue 15) see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine

2475-45-8 see Disperse Blue 1

2602-46-2 (C.I. direct blue 6) see Benzidine and Dyes Metabolized to Benzidine

3165-93-3 (p-chloro-o-toluidine hydrochloride) see p-Chloro-o-toluidine and Its Hydrochloride

3296-90-0 (2,2-bis(bromomethyl)-1,3-propanediol) see 2,2-Bis(bromomethyl)-1,3-propanediol (Technical Grade)

3697-24-3 (5-methylchrysene) see Polycyclic Aromatic Hydrocarbons: 15 Listings

4342-03-4 see Dacarbazine

4549-40-0 (N-nitrosomethylvinylamine) see N-Nitrosamines: 15 Listings

5278-95-5 (chlorodibromoacetic acid) see Haloacetic Acids Found as Water Disinfection By-Products (Selected)

5522-43-0 (1-nitropyrene) see Nitroarenes (Selected)

5589-96-8 (bromochloroacetic acid) see Haloacetic Acids Found as Water Disinfection By-Products (Selected)

6459-94-5 (C.I. acid red 114) see 3,3′-Dimethybenzidine and Dyes Metabolized to 3,3′-Dimethylbenzidine

7439-92-1 (lead) see Lead and Lead Compounds

7440-02-0 (nickel) see Nickel Compounds and Metallic Nickel

7440-38-2 (arsenic) see Arsenic and Inorganic Arsenic Compounds

7440-41-7 (beryllium) see Beryllium and Beryllium Compounds

7440-43-9 (cadmium) see Cadmium and Cadmium Compounds

7440-48-4 (cobalt) see Cobalt-Related Exposures

7446-27-7 (lead phosphate) see Lead and Lead Compounds

7446-34-6 see Selenium Sulﬁde

7496-02-8 (6-nitrochrysene) see Nitroarenes (Selected)

7631-89-2 (sodium arsenate) see Arsenic and Inorganic Arsenic Compounds

7646-79-9 (cobalt chloride) see Cobalt-Related Exposures

7664-93-9 (sulfuric acid) see Strong Inorganic Acid Mists Containing Sulfuric Acid

7775-11-3 (sodium chromate) see Chromium Hexavalent Compounds

7778-44-1 (calcium arsenate) see Arsenic and Inorganic Arsenic Compounds

7778-50-9 (potassium dichromate) see Chromium Hexavalent Compounds

7784-40-9 (lead arsenate) see Arsenic and Inorganic Arsenic Compounds

7784-46-5 (sodium arsenite) see Arsenic and Inorganic Arsenic Compounds

7786-81-4 (nickel sulfate) see Nickel and Nickel Compounds

7787-47-5 (beryllium chloride) see Beryllium and Beryllium Compounds

7787-56-6 (beryllium sulfate tetrahydrate) see Beryllium and Beryllium Compounds

7788-98-9 (ammonium chromate) see Chromium Hexavalent Compounds

7789-00-6 (potassium chromate) see Chromium Hexavalent Compounds

7789-06-2 (strontium chromate) see Chromium Hexavalent Compounds

7789-09-5 (ammonium dichromate) see Chromium Hexavalent Compounds

8001-35-2 see Toxaphene

8007-45-2 (coal tar) see Coal Tars and Coal-Tar Pitches

9004-66-4 see Iron Dextran Complex

10026-24-1 (cobalt sulfate heptahydrate) see Cobalt-Related Exposures

10034-93-2 (hydrazine sulfate) see Hydrazine and Hydrazine Sulfate

10043-92-2 (radon) see Ionizing Radiation

10108-64-2 (cadmium chloride) see Cadmium and Cadmium Compounds

10124-43-3 (cobalt sulfate) see Cobalt-Related Exposures

10141-05-6 (cobalt nitrate) see Cobalt-Related Exposures

10540-29-1 see Tamoxifen

10588-01-9 (sodium dichromate) see Chromium Hexavalent Compounds

11104-61-3 (cobalt oxide) see Cobalt-Related Exposures

11113-75-0 (nickel sulfide) see Nickel and Nickel Compounds

11119-70-3 (lead chromate) see Chromium Hexavalent Compounds

12001-28-4 (crocidolite) see Asbestos

12001-29-5 (chrysotile) see Asbestos

12035-72-2 (nickel subsulfide) see Nickel and Nickel Compounds

12054-48-7 (nickel hydroxide) see Nickel and Nickel Compounds

12126-59-9 (conjugated estrogens) see Estrogens, Steroidal

12172-73-5 (amosite) see Asbestos

12653-56-4 (cobalt sulfide) see Cobalt-Related Exposures

13010-47-4 (1-(2-chloroethyl)-3-cyclohexyl-1-nitrosourea) see Nitrosourea Chemotherapeutic Agents

13256-22-9 (N-nitrososarcosine) see N-Nitrosamines: 15 Listings

13327-32-7 (beryllium hydroxide) see Beryllium and Beryllium Compounds

13464-35-2 (potassium arsenite) see Arsenic and Inorganic Arsenic Compounds

13510-49-1 (beryllium sulfate) see Beryllium and Beryllium Compounds

13530-65-9 (zinc chromate) see Chromium Hexavalent Compounds

13552-44-8 (4-4′-methylenedianiline dihydrochloride) see 4,4′-Methylenedianiline and its Dihydrochloride

13598-00-0 (beryllium silicate) see Beryllium and Beryllium Compounds

13598-15-7 (beryllium phosphate) see Beryllium and Beryllium Compounds

13654-09-6 (decabromobiphenyl) see Polybrominated Biphenyls

13765-19-0 (calcium chromate) see Chromium Hexavalent Compounds

13909-09-6 (1-(2-chloroethyl)-3-(4-methylcyclohexyl)-1-nitrosourea) see Nitrosourea Chemotherapeutic Agents

14464-46-1 (cristobalite) see Silica

14808-60-7 (quartz) see Silica

15347-57-6 (lead acetate) see Lead and Lead Compounds

15468-32-3 (tridymite) see Silica

15663-27-1 see Cisplatin

16071-86-6 (C.I. direct brown 95) see Benzidine and Dyes Metabolized to Benzidine

16543-55-8 (N-nitrosonornicotine) see N-Nitrosamines: 15 Listings

18540-29-9 (chromium VI) see Chromium Hexavalent Compounds

18883-66-4 (streptozotocin) see Nitrosourea Chemotherapeutic Agents

23214-92-8 see Adriamycin

23246-96-0 see Riddelliine

25013-16-5 see Butylated Hydroxyanisole

25136-40-9 (doxorubicin hydrochloride) see Adriamycin

25638-88-4 (zinc beryllium silicate) see Beryllium and Beryllium Compounds

26471-62-5 see Toluene Diisocyanates

36355-01-8 (hexabromobiphenyl) see Polybrominated Biphenyls

39156-41-7 see 2,4-Diaminoanisole Sulfate

42397-64-8 (1,6-dinitropyrene) see Nitroarenes (Selected)

42397-65-9 (1,8-dinitropyrene) see Nitroarenes (Selected)

54749-90-5 (chlorozotocin) see Nitrosourea Chemotherapeutic Agents

57835-92-4 (4-nitropyrene) see Nitroarenes (Selected)

59865-13-3 see Cyclosporin A

61288-13-9 (octabromobiphenyl) see Polybrominated Biphenyls

64091-91-4 (4-(N-nitrosomethylamino)-1-(3-pyridyl)-1-butanone) see N-Nitrosamine Compounds: 15 Listings

65996-93-2 (coal-tar pitch) see Coal Tar and Coal-Tar Pitches

66104-24-3 (beryllium carbonate) see Beryllium and Beryllium Compounds

66733-21-9 see Erionite

71133-14-7 (bromodichloroacetic acid) see Haloacetic Acids Found as Water Disinfection By-Products (Selected)

76180-96-6 (2-amino-3-methylimidazo-[4,5-f]quinoline [IQ]) see Heterocyclic Amines (Selected)

77094-11-2 (2-amino-3,4-dimethylimidazo[4,5-f]quinoline [MeIQ]) see Heterocyclic Amines (Selected)

77500-04-0 (2-amino-3,8-dimethylimidazo[4,5-f]quinoxaline [MeIQx]) see Heterocyclic Amines (Selected)

77536-66-4 (actinolite) see Asbestos

77536-67-5 (anthophyllite) see Asbestos

77536-68-6 (tremolite) see Asbestos

105650-23-5 (2-amino-1-methyl-6-phenylimidazo[4,5-b]pyridine [PhIP]) see Heterocyclic Amines (Selected)

108171-26-2 see Chlorinated Paraffins (C_12_, 60% Chlorine)