# Appendix F Substance Names and Common Synonyms

A

2-AAF see 2-Acetylaminofluorene

ABP see 4-Aminobiphenyl

ABVD therapy see Dacarbazine

ADBAQ see 1-Amino-2,4-dibromoanthraquinone

AFB1 see Aflatoxins

As see Arsenic and Inorganic Arsenic Compounds

ATO see Antimony Trioxide

5-AzaC see Azacitidine

2-acetamidofluorene see 2-Acetylaminofluorene

2-acetaminofluorene see 2-Acetylaminofluorene

acetate blue G see Disperse Blue 1

acetic aldehyde see Acetaldehyde

acetothioamide see Thioacetamide

acetylaldehyde see Acetaldehyde

acetylhydride see Acetaldehyde

acid red 114 (C.I.) see 3,3′-Dimethylbenzidine and Dyes Metabolized to 3,3′-Dimethylbenzidine, Dyes Metabolized to 3,3′-Dimethylbenzidine

aciniform carbon see Soots

acrylic acid amide see Acrylamide

actinolite see Asbestos

actinon see Ionizing Radiation, Radon

alcohol drinking see Alcoholic Beverage Consumption

aluminum-beryllium alloy see Beryllium and Beryllium Compounds

o-aminoanisole see o-Anisidine and Its Hydrochloride

2-aminoanisole hydrochloride see o-Anisidine and Its Hydrochloride

2-amino-9,10-anthracenedione see 2-Aminoanthraquinone

β-aminoanthraquinone see 2-Aminoanthraquinone

2-aminoazotoluene see o-Aminoazotoluene

p-aminobiphenyl see 4-Aminobiphenyl

2-amino-3,4-dimethylimidazo[4,5-f]quinoline see Heterocyclic Amines (Selected)

2-amino-3,8-dimethylimidazo[4,5-f]quinoxaline see Heterocyclic Amines (Selected)

4-aminodiphenyl see 4-Aminobiphenyl

p-aminodiphenyl see 4-Aminobiphenyl

para-aminodiphenyl see 4-Aminobiphenyl

1-amino-2-methyl-9,10-anthracenedione see 1-Amino-2-methylanthraquinone

2-amino-3-methyl-3H-imidazo(4,5-f)quinoline see Heterocyclic Amines (Selected), 2-Amino-3-methylimidazo[4,5-f]quinoline (IQ)

2-amino-1-methyl-6-phenylimidazo[4,5-b]pyridine see Heterocyclic Amines (Selected)

2-amino-3-methylimidazo[4,5-f]quinoline see Heterocyclic Amines (Selected)

4-[(4-aminophenyl)(4-imino-2,5-cyclohexadien-1-ylidene)methyl]-benzenamine, monohydrochloride see Basic Red 9 Monohydride

4-amino-1-β-D-ribofuranosyl-1,3,5-triazin-2(1H)-one see Azacitidine

3-amino-1,2,4-triazol see Amitrole

aminotriazole see Amitrole

amosite see Asbestos

analgesic mixtures containing phenacetin see Phenacetin and Analgesic Mixtures Containing Phenacetin

2-anisidine hydrochloride see o-Anisidine and Its Hydrochloride

anthophyllite see Asbestos

Aroclor 1016 see Polychlorinated Biphenyls

Aroclor 1221 see Polychlorinated Biphenyls

Aroclor 1242 see Polychlorinated Biphenyls

Aroclor 1248 see Polychlorinated Biphenyls

Aroclor 1254 see Polychlorinated Biphenyls

Aroclor 1260 see Polychlorinated Biphenyls

Aroclor 1262 see Polychlorinated Biphenyls

arsanilic acid see Arsenic and Inorganic Arsenic Compounds

arsenate see Arsenic and Inorganic Arsenic Compounds

arsenite see Arsenic and Inorganic Arsenic Compounds

arsenous oxide see Arsenic and Inorganic Arsenic Compounds

arsenous trichloride see Arsenic and Inorganic Arsenic Compounds

arsine see Arsenic and Inorganic Arsenic Compounds

5-azacytidine see Azacitidine

B

B-1 glass fibers see Certain Glass Wool Fibers (Inhalable)

B-09 glass fibers see Certain Glass Wool Fibers (Inhalable)

B-20 glass fibers see Certain Glass Wool Fibers (Inhalable)

BA see Polycyclic Aromatic Hydrocarbons: 15 Listings, Benz[a]anthracene

B[a]P see Polycyclic Aromatic Hydrocarbons: 15 Listings, Benzo[a]pyrene

BB-153 (hexabromobiphenyl) see Polybrominated Biphenyls

B[b]F see Polycyclic Aromatic Hydrocarbons: 15 Listings, Benzo[b]fluoranthene

BBMP see 2,2-Bis(bromomethyl)-1,3-propanediol (Technical Grade)

BCME see Bis(chloromethyl) Ether and Technical-Grade Chloromethyl Methyl Ether

BCNU see Nitrosourea Chemotherapeutic Agents, Bis(chloroethyl) Nitrosourea

Be see Beryllium and Beryllium Compounds

BHA see Butylated Hydroxyanisole

B[j]F see Polycyclic Aromatic Hydrocarbons: 15 Listings, Benzo[j]fluoranthene

B[k]F see Polycyclic Aromatic Hydrocarbons: 15 Listings, Benzo[k]fluoranthene

basic fuchsin see Basic Red 9 Monohydride

basic red 9 see Basic Red 9 Monohydride

basic red 9 monohydrochloride (C.I.) see Basic Red 9 Monohydride

basic zinc chromate see Chromium Hexavalent Compounds

beer see Alcoholic Beverage Consumption

1,2-benzanthracene see Polycyclic Aromatic Hydrocarbons: 15 Listings, Benz[a]anthracene

benz[a]anthracene see Polycyclic Aromatic Hydrocarbons: 15 Listings

benz[a]anthracine see Polycyclic Aromatic Hydrocarbons: 15 Listings, Benz[a]anthracene

benz[e]acephenanthrylene see Polycyclic Aromatic Hydrocarbons: 15 Listings, Benzo[b]fluoranthene

benzidine dye class see Benzidine and Dyes Metabolized to Benzidine, Dyes Metabolized to Benzidine

benzo[b]fluoranthene see Polycyclic Aromatic Hydrocarbons: 15 Listings

benzo[j]fluoranthene see Polycyclic Aromatic Hydrocarbons: 15 Listings

benzo[k]fluoranthene see Polycyclic Aromatic Hydrocarbons: 15 Listings

benzoic trichloride see Benzotrichloride

benzol see Benzene

benzo[rst]pentaphene see Polycyclic Aromatic Hydrocarbons: 15 Listings, Dibenzo[a,i]pyrene

benzo[a]pyrene see Polycyclic Aromatic Hydrocarbons: 15 Listings

beryl ore see Beryllium and Beryllium Compounds

beta-aminoanthraquinone see 2-Aminoanthraquinone

beta-naphthylamine see 2-Naphthylamine

bidis see Tobacco-Related Exposures, Tobacco Smoking

2,2′-bioxirane see Diepoxybutane

4-biphenylamine see 4-Aminobiphenyl

2,2-bis(bromomethyl)propane-1,3-diol see 2,2-Bis(bromomethyl)-1,3-propanediol (Technical Grade)

bischloroethyl nitrosourea see Nitrosourea Chemotherapeutic Agents, Bis(chloroethyl) Nitrosourea

4-[bis(2-chloroethyl)amino]-L-phenylalanine see Melphalan

4-[p-[bis(2-chloroethyl)amino]phenyl]butyric acid see Chlorambucil

bis(2-chloroethyl)sulfide see Mustard Gas

4-[bis(2-chlomethyl)amino]benzenebutanoic acid see Chlorambucil

4,4′-bis(dimethylamino)benzophenone see Michler’s Ketone

bis(2-ethylhexyl) ester 1,2-benzenedicarboxylic acid see Di(2-ethylhexyl) Phthalate

bis(2-ethylhexyl phthalate) see Di(2-ethylhexyl) Phthalate

3,3-bis(4-hydroxyphenyl)-1-(3H)-isobenzofuranone see Phenolphthalein

broad-spectrum ultraviolet radiation see Ultraviolet Radiation Related Exposures

bromochloroacetic acid see Haloacetic Acids Found as Water Disinfection By-products (Selected)

bromodichloroacetic acid see Haloacetic Acids Found as Water Disinfection By-products (Selected)

bromoethene see Vinyl Halides (Selected), Vinyl Bromide

bromoiodoacetic acid see Haloacetic Acids Found as Water Disinfection By-products (Selected)

busulfan see 1,4-Butanediol Dimethanesulfonate

Busulfex see 1,4-Butanediol Dimethanesulfonate

1,3-butadiene diepoxide see Diepoxybutane

butane diepoxide see Diepoxybutane

1,4-butanediol dimethanesulphonate see 1,4-Butanediol Dimethanesulfonate

butter yellow see 4-Dimethylaminoazobenzene

C

Cd see Cadmium and Cadmium Compounds

CEP see Epichlorohydrin

C.I. 42500 see Basic Red 9 Monohydrochloride

C.I. 64500 see Disperse Blue 1

C.I. acid red 114 see 3,3ʹ-Dimethylbenzidine and Dyes Metabolized to 3,3ʹ-Dimethylbenzidine, Dyes Metabolized to 3,3ʹ-Dimethoxybenzidine

C.I. basic red monohydrochloride see Basic Red 9 Monohydrochloride

C.I. direct black 38 see Benzidine and Dyes Metabolized to Benzidine, Dyes Metabolized to Benzidine

C.I. disperse blue 1 see Disperse Blue 1

C.I. direct blue 6 see Benzidine and Dyes Metabolized to Benzidine, Dyes Metabolized to Benzidine

C.I. direct blue 15 see 3,3ʹ-Dimethoxybenzidine and Dyes Metabolized to 3,3ʹ-Dimethoxybenzidine, Dyes Metabolized to 3,3ʹ-Dimethoxybenzidine

C.I. direct brown 95 see Benzidine and Dyes Metabolized to Benzidine, Dyes Metabolized to Benzidine

C.I. disperse orange see 1-Amino-2-methylanthraquinone

C.I. solvent yellow 3 see o-Aminoazotoluene

CCNU see Nitrosourea Chemotherapeutic Agents, 1-(2-Chloroethyl)-3-cyclohexyl-1-nitrosourea

CMME see Bis(chloromethyl) Ether and Technical-Grade Chloromethyl Methyl Ether

Co see Cobalt-Related Exposures, Cobalt and Cobalt Compounds That Release Cobalt Ions In Vivo

Co/WC see Cobalt-Related Exposures, Cobalt-Tungsten Carbide: Powders and Hard Metals

calcium arsenate see Arsenic and Inorganic Arsenic Compounds

calcium arsenite see Arsenic and Inorganic Arsenic Compounds

calcium chromate see Chromium Hexavalent Compounds

camphechlor see Toxaphene

carbamic acid ethyl ester see Urethane

carbamodithioic acid, diethyl-, 2-chloro-2-propenyl ester see Sulfallate

carbon cenospheres see Soots

carbonaceous xerogol particles see Soots

carmustine see Nitrosourea Chemotherapeutic Agents, Bis(chloroethyl) Nitrosourea

cemented carbides see Cobalt-Related Exposures, Cobalt-Tungsten Carbide: Powders and Hard Metals

CertainTeed B glass fiber see Certain Glass Wool Fibers (Inhalable)

chewing tobacco see Tobacco-Related Exposures, Smokeless Tobacco

chinofer see Iron Dextran Complex

2-chlorallyl diethyldithiocarbamate see Sulfallate

chlordecone see Kepone

chlorethamine see Nitrogen Mustard Hydrochloride

chlorinated camphene see Toxaphene

4-chloro-1,2-benzenediamine see 4-Chloro-o-phenylenediamine

2-chloro-1,3-butadiene see Chloroprene

chlorocamphene see Toxaphene

2-chloro-N-(2-chloroethyl)-N-methylethanamine see Nitrogen Mustard Hydrochloride

chlorodibromoacetic acid see Haloacetic Acids Found as Water Disinfection By-products (Selected)

1-chloro-2,3-dibromopropane see 1,2-Dibromo-3-chloropropane

3-chloro-1,2-dibromopropane see 1,2-Dibromo-3-chloropropane

chlorodiphenyls see Polychlorinated Biphenyls

1-chloro-2,3-epoxypropane see Epichlorohydrin

chloroethene see Vinyl Halides (Selected), Vinyl Chloride

2-((((2-chloroethyl)nitrosoamino)carbonyl)amino)-2-deoxy-D-glucose see Nitrosourea Chemotherapeutic Agents, Chlorozotocin

chloroiodoacetic acid see Haloacetic Acids Found as Water Disinfection By-products (Selected)

chloromethyl methyl ether see Bis(chloromethyl) Ether and Technical-Grade Chloromethyl Methyl Ether

chloromethyl oxirane see Epichlorohydrin

4-chloro-2-methylaniline see p-Chloro-o-toluidine and Its Hydrochloride

4-chloro-2-methylbenzenamine see p-Chloro-o-toluidine and Its Hydrochloride

4-chloro-2-methylbenzenamine hydrochloride see p-Chloro-o-toluidine and Its Hydrochloride

1-chloro-2-methylpropene see Dimethylvinyl Chloride

1-chloro-2-methyl-1-propene see Dimethylvinyl Chloride

3-chloro-2-methyl-1-propene see 3-Chloro-2-methylpropene

4-chloro-1,2-phenylenediamine see 4-Chloro-o-phenylenediamine

4-chloro-o-toluidine see p-Chloro-o-toluidine and Its Hydrochloride

4-chloro-o-toluidine hydrochloride see p-Chloro-o-toluidine and Its Hydrochloride

chromated copper arsenate (CCA) see Arsenic and Inorganic Arsenic Compounds and Chromium Hexavalent Compounds

chromates see Chromium Hexavalent Compounds

chromic trioxide see Chromium Hexavalent Compounds

chromium VI see Chromium Hexavalent Compounds

chrysazin see Danthron

chrysotile see Asbestos

ciclosporin see Cyclosporin A

cigarettes see Tobacco-Related Exposures, Tobacco Smoking

cigars see Tobacco-Related Exposures, Tobacco Smoking

cis-dichlorodiamine platinum (II) see Cisplatin

cis-1,3-dichloropropene see 1,3-Dichloropropene (Technical Grade)

Clophen A see Polychlorinated Biphenyls

Clophens see Polychlorinated Biphenyls

coal tar distillates see Coal Tars and Coal Tar Pitches

cobalt see Cobalt-Related Exposures, Cobalt and Cobalt Compounds That Release Cobalt Ions In Vivo

coke and char fragments see Soots

conjugated estrogens see Estrogens, Steroidal

copper-beryllium alloy see Beryllium and Beryllium Compounds

cristobalite see Silica, Crystalline (Respirable Size)

crocidolite see Asbestos

crystalline quartz see Silica, Crystalline (Respirable Size)

crystalline silica, respirable see Silica, Crystalline (Respirable Size)

crystalline silicon dioxide see Silica, Crystalline (Respirable Size)

(R-(R*,R*-(E)))-cyclic(L-alanyl-D-alanyl-N-methyl-L-leucyl-N-methyl-L-leucyl-N-methyl-L-valyl-3-hydroxy-N,4-dimethyl-L-2-amino-6-octenoyl-L-α-aminobutyryl-N-methylglycyl-N-methyl-L-leucyl-L-valyl-N-methyl-L-leucyl) see Cyclosporin A

cyclosporine see Cyclosporin A

D

DAAB see Diazoaminobenzene

DB[a,e]P see Polycyclic Aromatic Hydrocarbons: 15 Listings, Dibenzo[a,e]pyrene

DB[a,h]A see Polycyclic Aromatic Hydrocarbons: 15 Listings, Dibenz[a,h]anthracene

DB[a,h]P see Polycyclic Aromatic Hydrocarbons: 15 Listings, Dibenzo[a,h]pyrene

DB[a,h]AC see Polycyclic Aromatic Hydrocarbons: 15 Listings, Dibenz[a,h]acridine

DB[a,i]P see Polycyclic Aromatic Hydrocarbons: 15 Listings, Dibenzo[a,i]pyrene

DB[a,j]AC see Polycyclic Aromatic Hydrocarbons: 15 Listings, Dibenz[a,j]acridine

DB[a,l]P see Polycyclic Aromatic Hydrocarbons: 15 Listings, Dibenzo[a,l]pyrene

DBCP see 1,2-Dibromo-3-chloropropane

DBP see 2,3-Dibromo-1-propanol

DDT see Dichlorodiphenyltrichloroethane

o-o′-DDT see Dichlorodiphenyltrichloroethane

o-p′-DDT see Dichlorodiphenyltrichloroethane

p,p′-DDT see Dichlorodiphenyltrichloroethane

DEHP see Di(2-ethylhexyl) Phthalate

DEN see N-Nitrosamines: 15 Listings, N-Nitrosodiethylamine

DES see Diethylstilbestrol

DMN see N-Nitrosamines: 15 Listings, N-Nitrosodimethylamine

dantron see Danthron

decabromobiphenyl see Polybrominated Biphenyls

1,1a,3,3a,4,5,5,5a,5b,6-decachlorooctahydro-1,3,4-metheno-2H-cyclobuta[cd]pentalen-2-one see Kepone

2-deoxy-2((methyl-nitrosoamino)carbonyl)amino)-D-glucopyranose see Nitrosourea Chemotherapeutic Agents, Streptozotocin

dextran iron complex see Iron Dextran Complex

4,4′-diaminobiphenyl see Benzidine

4,4′-diaminodiphenyl ether see 4,4′-Oxydianiline

diaminodiphenyl ether see 4,4′-Oxydianiline

4,4′-diaminodiphenyl sulfide see 4,4′-Thiodianiline

4,4′-diaminodiphenylmethane see 4,4′-Methylenedianiline and Its Dihydrochloride

o-dianisidine see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine, Dyes Metabolized to 3,3′-Dimethoxybenzidine

diantimony trioxide see Antimony Trioxide

dibenz[a,h]acridine see Polycyclic Aromatic Hydrocarbons: 15 Listings

dibenz[a,j]acridine see Polycyclic Aromatic Hydrocarbons: 15 Listings

dibenz[a,h]anthracene see Polycyclic Aromatic Hydrocarbons: 15 Listings

7H-dibenzo[c,g]carbazole see Polycyclic Aromatic Hydrocarbons: 15 Listings

dibenzo[b,c,e,f]chrysene see Polycyclic Aromatic Hydrocarbons: 15 Listings, Dibenzo[a,h]pyrene

dibenzo[def,p]chrysene see Polycyclic Aromatic Hydrocarbons: 15 Listings, Dibenzo[a,l]pyrene

1,2,4,5-dibenzopyrene see Polycyclic Aromatic Hydrocarbons: 15 Listings, Dibenzo[a,e]pyrene

3,4,9,10-dibenzopyrene see Polycyclic Aromatic Hydrocarbons: 15 Listings, Dibenzo[a,i]pyrene

dibenzo[a,e]pyrene see Polycyclic Aromatic Hydrocarbons: 15 Listings

dibenzo[a,h]pyrene see Polycyclic Aromatic Hydrocarbons: 15 Listings

dibenzo[a,i]pyrene see Polycyclic Aromatic Hydrocarbons: 15 Listings

dibenzo[a,l]pyrene see Polycyclic Aromatic Hydrocarbons: 15 Listings

2,4-dibromo-1-anthraquinonylamine see 1-Amino-2,4-dibromoanthraquinone

dibromoneopentyl glycol see 2,2-Bis(bromomethyl)-1,3-propanediol (Technical Grade)

2,3-dibromopropanol see 2,3-Dibromo-1-propanol

2,3-dibromopropan-1-ol see 2,3-Dibromo-1-propanol

2,3-dibromo-1-propanol phosphate (3:1) see Tris(2,3-dibromopropyl) Phosphate

dichloroacetic acid see Haloacetic Acids Found as Water Disinfection By-products (Selected)

p-dichlorobenzene see 1,4-Dichlorobenzene

3,3′-dichloro-(1,1′-biphenyl)-4,4′-diamine see 3,3′-Dichlorobenzidine and Its Dihydrochloride

3,3′-dichloro-(1,1′-biphenyl)-4,4′-diamine dihydrochloride see 3,3′-Dichlorobenzidine and Its Dihydrochloride

dichlorobromomethane see Bromodichloromethane

dichlorodimethyl ether, symmetrical see Bis(chloromethyl) Ether and Technical-Grade Chloromethyl Methyl Ether

2,2-dichloro-N-(2-hydroxy-1-(hydroxymethyl)-2-(4-nitrophenyl)ethyl)-, (R-(R*,R*))-nitrophenyl)ethyl]acetamide see Chloramphenicol

[R-(R*,R*)]-2,2-dichloro-N-[2-hydroxy-1-(hydroxymethyl)-2-(4-nitrophenyl)ethyl]acetamide see Chloramphenicol

2,4-dichloro-1-(4-nitrophenoxy)benzene see Nitrofen

2,4-dichlorophenyl-p-nitrophenyl ether see Nitrofen

1,3-dichloro-1-propene see 1,3-Dichloropropene (Technical Grade)

(E)-1,3-dichloropropene see 1,3-Dichloropropene (Technical Grade)

(Z)-1,3-dichloropropene see 1,3-Dichloropropene (Technical Grade)

dichromates see Chromium Hexavalent Compounds

1,2:3,4-diepoxybutane see Diepoxybutane

diethyl ester sulfuric acid see Diethyl Sulfate

diethyl sulphate see Diethyl Sulfate

(E)-4,4′-(1,2-diethyl-1,2-ethenediyl)bisphenol see Diethylstilbestrol

diethylhexyl phthalate see Di(2-ethylhexyl) Phthalate

diethylnitrosamine see N-Nitrosamines: 15 Listings, N-Nitrosodiethylamine

Diethylstilboestrol see Diethylstilbestrol

Difolatan see Captafol

2,3-dihydro-6-propyl-2-thioxo-4(1H)-pyrimidinone see Propylthiouracil

1,8-dihydroxy-9,10-anthracenedione see Danthron

1,8-dihydroxyanthraquinone see Danthron

diiodoacetic acid see Haloacetic Acids Found as Water Disinfection By-products (Selected)

1,3-diisocyanatomethylbenzene see Toluene Diisocyanates

Dilantin see Phenytoin and Phenytoin Sodium

3,3′-dimethoxybenzidine dye class see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine, Dyes Metabolized to 3,3′-Dimethoxybenzidine

dimethyl ester sulfuric acid see Dimethyl Sulfate

p-dimethylaminoazobenzene see 4-Dimethylaminoazobenzene

para-dimethylaminoazobenzene see 4-Dimethylaminoazobenzene

4,4′-(dimethylamino)benzophenone see Michler’s Ketone

3,3′-dimethylbenzidine dye class see 3,3′-Dimethylbenzidine and Dyes Metabolized to 3,3′-Dimethylbenzidine, Dyes Metabolized to 3,3′-Dimethylbenzidine

dimethylcarbamic chloride see Dimethylcarbamoyl Chloride

(1,1-dimethylethyl)-4-methoxyphenol see Butylated Hydroxyanisole

dimethylnitrosamine see N-Nitrosamines: 15 Listings, N-Nitrosodimethylamine

3,4-dimethyl-3H-imidazo[4,5-f]quinolin-2-amine see Heterocyclic Amines (Selected), 2-Amino-3,4-dimethylimidazo[4,5-f]quinoline (MeIQ)

3,8-dimethyl-3H-imidazo[4,5-f]quinoxalin-2-amine see Heterocyclic Amines (Selected), 2-Amino-3,8-dimethylimidazo[4,5-f]quinoxaline (MeIQx)

5-(3,3-dimethyl-1-triazenyl)1H-imidazole-4-carboxamide see Dacarbazine

1,6-dinitropyrene see Nitroarenes (Selected)

1,8-dinitropyrene see Nitroarenes (Selected)

dioctyl phthalate see Di(2-ethylhexyl) Phthalate

di-sec-octyl phthalate see Di(2-ethylhexyl) Phthalate

dioxin see 2,3,7,8-Tetrachlorodibenzo-p-dioxin

diphenylan see Phenytoin and Phenytoin Sodium

(Z)-2-[4-(1,2-diphenyl-1-butenyl)phenoxy]-N,N-dimethylethanamine see Tamoxifen

diphenylhydantoin see Phenytoin and Phenytoin Sodium

5,5-diphenylhydantoin see Phenytoin and Phenytoin Sodium

1,2-diphenylhydrazine see Hydrazobenzene

5,5-diphenyl-2,4-imidazolidinedione see Phenytoin and Phenytoin Sodium

1,3-diphenyltriazene see Diazoaminobenzene

direct black 38 (C.I.) see Benzidine and Dyes Metabolized to Benzidine, Dyes Metabolized to Benzidine

direct blue 1 (C.I.) see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine, Dyes Metabolized to 3,3′-Dimethoxybenzidine

direct blue 2 (C.I.) see Benzidine and Dyes Metabolized to Benzidine

direct blue 6 (C.I.) see Benzidine and Dyes Metabolized to Benzidine, Dyes Metabolized to Benzidine

direct blue 8 (C.I.) see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine, Dyes Metabolized to 3,3′-Dimethoxybenzidine

direct blue 14 (C.I.) see 3,3′-Dimethylbenzidine and Dyes Metabolized to 3,3′-Dimethylbenzidine, Dyes Metabolized to 3,3′-Dimethylbenzidine

direct blue 15 (C.I.) see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine, Dyes Metabolized to 3,3′-Dimethoxybenzidine

direct blue 76 (C.I.) see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine, Dyes Metabolized to 3,3′-Dimethoxybenzidine

direct blue 98 (C.I.) see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine, Dyes Metabolized to 3,3′-Dimethoxybenzidine

direct blue 218 (C.I.) see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine, Dyes Metabolized to 3,3′-Dimethoxybenzidine

direct brown 2 (C.I.) see Benzidine and Dyes Metabolized to Benzidine, Dyes Metabolized to Benzidine

direct brown 95 (C.I.) see Benzidine and Dyes Metabolized to Benzidine, Dyes Metabolized to Benzidine

direct green 6 (C.I.) see Benzidine and Dyes Metabolized to Benzidine, Dyes Metabolized to Benzidine

direct red 28 (C.I.) see Benzidine and Dyes Metabolized to Benzidine, Dyes Metabolized to Benzidine

disodium hydrogen arsenate see Arsenic and Inorganic Arsenic Compounds

disperse orange see 1-Amino-2-methylanthraquinone

1,1a,2,2,3,3a,4,5,5,5a,5b,6-dodecachlorooctahydro-1,3,4-metheno-lH-cyclobuta(cd)pentalene see Mirex

Dowicide EC-7 see Pentachlorophenol and By-products of Its Synthesis

doxorubicin hydrochloride see Adriamycin

dyes metabolized to benzidine see Benzidine and Dyes Metabolized to Benzidine, Dyes Metabolized to Benzidine

dyes metabolized to 3,3′-dimethoxybenzidine see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine, Dyes Metabolized to3,3′-Dimethoxybenzidine

dyes metabolized to 3,3′-dimethylbenzidine see 3,3′-Dimethylbenzidine and Dyes Metabolized to 3,3′-Dimethylbenzidine, Dyes Metabolized to 3,3′-Dimethylbenzidine

E

EBV see Viruses (Selected), Epstein-Barr Virus

EDB see 1,2-Dibromoethane

ENU see N-Nitrosamines: 15 Listings, N-Nitroso-N-ethylurea

ETS see Tobacco-Related Exposures, Environmental Tobacco Smoke

ETU see Ethylene Thiourea

E-glass fibers see Certain Glass Wool Fibers (Inhalable)

environmental tobacco smoke see Tobacco-Related Exposures

1,2-epoxyethylbenzene see Styrene-7,8-oxide

1-epoxyethyl-3,4-epoxycyclohexane see 4-Vinyl-1-cyclohexene Diepoxide

estradiol see Estrogens, Steroidal

estrone see Estrogens, Steroidal

ethanal see Acetaldehyde

ethanol see Alcoholic Beverage Consumption

ethinylestradiol see Estrogens, Steroidal

ethyl aldehyde see Acetaldehyde

ethyl carbamate see Urethane

ethyl methanesulphonate see Ethylmethanesulfonate

ethylene dibromide see 1,2-Dibromoethane

ethylene dichloride see 1,2-Dichloroethane

ethylenethiourea see Ethylene Thiourea

1-ethyl-1-nitrosourea see N-Nitrosamines: 15 Listings, N-Nitroso-N-ethylurea

eugenol methyl ether see Methyleugenol

F

FF-1 see Polybrominated Biphenyls

fast garnet GBC base see o-Aminoazotoluene

ferrochromium see Chromium Hexavalent Compounds

FG insulation fiberglass see Certain Glass Wool Fibers (Inhalable)

FireMaster BP-6 see Polybrominated Biphenyls

FireMaster FF1 see Polybrominated Biphenyls

Firemaster t 23 see Tris(2,3-dibromopropyl) Phosphate

flavatoxin see Aflatoxins

2-fluorenylacetamide see 2-Acetylaminofluorene

fluoroethene see Vinyl Halides (Selected), Vinyl Fluoride

formalin see Formaldehyde

Fosphenytoin see Phenytoin and Phenytoin Sodium

G

gamma radiation see Ionizing Radiation, X-Radiation and Gamma Radiation

gamma-hexachlorocyclohexane see Lindane, Hexachlorocyclohexane (Technical Grade), and Other Hexachlorocyclohexane Isomers

glass code 104 see Certain Glass Wool Fibers (Inhalable)

glass code 108b see Certain Glass Wool Fibers (Inhalable)

glass code 110 see Certain Glass Wool Fibers (Inhalable)

glass wool fiber B see Certain Glass Wool Fibers (Inhalable)

glass wool fiber P see Certain Glass Wool Fibers (Inhalable)

glass wool fiber V see Certain Glass Wool Fibers (Inhalable)

glycidaldehyde see Glycidol

H

7H-DB[c,g]C see Polycyclic Aromatic Hydrocarbons: 15 Listings, 7H-Dibenzo[c,g]carbazole

7H-dibenzo[c,g]carbazole see Polycyclic Aromatic Hydrocarbons: 15 Listings

HAAs see Haloacetic Acids Found as Water Disinfection By-products (Selected)

HBV see Viruses (Selected), Hepatitis B Virus

HCAs see Heterocyclic Amines (Selected)

HCH see Lindane, Hexachlorocyclohexane (Technical Grade), and Other Hexachlorocyclohexane Isomers

HCV see Viruses (Selected), Hepatitis C Virus

HHV-4 see Viruses (Selected), Epstein-Barr Virus

HHV-8 see Viruses (Selected), Kaposi Sarcoma-Associated Herpesvirus

HIV-1 see Viruses (Selected), Human Immunodeficiency Virus Type 1

HMPA see Hexamethylphophoramide

HPV see Human Papillomaviruses: Some Genital-Mucosal Types

H. pylori see Helicobacter pylori (chronic infection)

HTLV-1 see Viruses (Selected), Human T-Cell Lymphotropic Virus Type 1

hard metals see Cobalt-Related Exposures, Cobalt–Tungsten Carbide: Powders and Hard Metals

heptabromobiphenyls see Polybrominated Biphenyls

heptachlorobiphenyls see Polychlorinated Biphenyls

hexabromobiphenyls see Polybrominated Biphenyls

1,4,5,6,7,7-hexa-chlorobicyclo[2.2.1]hept-5-ene-2,3-dicarboxylic acid see Chlorendic Acid

hexachlorobiphenyls see Polychlorinated Biphenyls

hexachlorocyclohexane see Lindane, Hexachlorocyclohexane (Technical Grade), and Other Hexachlorocyclohexane Isomers

γ-hexachlorocyclohexane see Lindane, Hexachlorocyclohexane (Technical Grade), and Other Hexachlorocyclohexane Isomers

hexachlorocyclohexane isomers see Lindane, Hexachlorocyclohexane (Technical Grade), and Other Hexachlorocyclohexane Isomers

hexamethylphosphoric triamide see Hexamethylphosphoramide

hexavalent chromium compounds see Chromium Hexavalent Compounds

human herpesvirus 4 see Epstein-Barr Virus

human herpesvirus 8 see Kaposi Sarcoma-Associated Herpesvirus

14-hydroxydaunomycin see Adriamycin

17-hydroxy-2-(hydroxymethylene)-17-methyl-5α,17β-androstan-3-one see Oxymetholone

(17α)-17-hydroxy-19-norpregn-4-en-20-yn-3-one see Norethisterone

I

IP see Indeno[1,2,3-cd]pyrene

IQ see Heterocyclic Amines (Selected), 2-Amino-3-methylimidazo[4,5-f]quinoline

2-imidazolidinethione see Ethylene Thiourea

indeno[1,2,3-cd]pyrene see Polycyclic Aromatic Hydrocarbons: 15 Listings

Infed see Iron Dextran Complex

inorganic acid mists see Strong Inorganic Acid Mists Containing Sulfuric Acid

insulation glass fibers see Certain Glass Wool Fibers (Inhalable)

involuntary smoking see Tobacco-Related exposure, Environmental Tobacco Smoke

iron-carbohydrate complexes see Iron Dextran Complex

isocyanic acid see Toluene Diisocyanates

isopropylbenzene see Cumene

J

JM 104/475 glass fibers see Certain Glass Wool Fibers (Inhalable)

K

KSHV see Viruses (Selected), Kaposi Sarcoma–Associated Herpesvirus

Kanechlor 500 see Polychlorinated Biphenyls

L

lead acetate see Lead and Lead Compounds

lead arsenate see Arsenic and Inorganic Arsenic Compounds

lead chromates see Chromium Hexavalent Compounds and Lead and Lead Compounds

lead phosphate see Lead and Lead Compounds

lomustine see Nitrosourea Chemotherapeutic Agents, 1-(2-Chloroethyl)-3-cyclohexyl-1-nitrosourea

lubricant base oils see Mineral Oils: Untreated and Mildly Treated

M

MBOCA see 4,4′-Methylenebis(2-chloroaniline)

5-MC see Polycyclic Aromatic Hydrocarbons: 15 Listings, 5-Methylchrysene

MCPyV see Viruses (Selected), Merkel Cell Polyomavirus

MCV see Viruses (Selected), Merkel Cell Polyomavirus

MeCCNU see Nitrosourea Chemotherapeutic Agents, 1-(2-Chloroethyl)-3-(4-methylcyclohexyl)-1-nitrosourea

MeIQ see Heterocyclic Amines (Selected), 2-Amino-3,4-dimethylimidazo[4,5-f]quinoline

MeIQx see Heterocyclic Amines (Selected), 2-Amino-3,8-dimethylimidazo-[4,5-f]quinoxaline

MMVF 33 glass fibers see Certain Glass Wool Fibers (Inhalable)

MMVF 10 see Certain Glass Wool Fibers (Inhalable)

MMVF 10a see Certain Glass Wool Fibers (Inhalable)

MMVF 11 see Certain Glass Wool Fibers (Inhalable)

MNNG see N-Nitrosamines: 15 Listings, N-Methyl-N′-nitro-N-nitrosoguanidine

MOCA see 4,4′-Methylenebis(2-chloroaniline)

MOPP see Nitrogen Mustard Hydrochloride and Procarbazine and Its Hydrochloride

MVNA see N-Nitrosamines: 15 Listings, N-Nitrosomethylvinylamine

mainstream smoke see Tobacco-Related Exposures, Environmental Tobacco Smoke

man-made mineral fibers see Ceramic Fibers (Respirable Size) and Certain Glass Wool Fibers (Inhalable)

Manville 901 glass fiber see Certain Glass Wool Fibers (Inhalable)

mechlorethamine see Nitrogen Mustard Hydrochloride

mechlorethamine hydrochloride see Nitrogen Mustard Hydrochloride

mestranol see Estrogens, Steroidal

metallic arsenic see Arsenic and Inorganic Arsenic Compounds

metallic nickel see Nickel Compounds and Metallic Nickel

methallyl chloride see 3-Chloro-2-methylpropene

4-methoxy-1,3-benzenediamine see 2,4-Diaminoanisole Sulfate

9-methoxy-7H-furo [3,2g] [1] benzopyran-7-one see Methoxsalen with Ultraviolet A Therapy

2-methoxy-5-methylbenzenamine see p-Cresidine

1-methoxy-2-nitrobenzene see o-Nitroanisole

4-methoxy-m-phenylenediamine sulfate see 2,4-Diaminoanisole Sulfate

2-methoxybenzenamine see o-Anisidine and Its Hydrochloride

8-methoxypsoralen see Methoxsalen with Ultraviolet A Therapy

methyl chloromethyl ether see Bis(chloromethyl) Ether and Technical-Grade Chloromethyl Methyl Ether

methyl ester methanesulfonic acid see Methyl Methanesulfonate

methyl eugenol see Methyleugenol

methyl 18β-hydroxy-11,17α-dimethoxy-3β,20α-yohimban-16β-carboxylate 3,4,5-trimethoxybenzoate (ester) see Reserpine

2-methylbenzenamine see o-Toluidine

4-methyl-1,3-benzenediamine see 2,4-Diaminotoluene

2-methyl-1,3-butadiene see Isoprene

methyl-CCNU see Nitrosourea Chemotherapeutic Agents, 1-(2-Chloroethyl)-3-(4-methylcyclohexyl)-1-nitrosourea

5-methylchrysene see Polycyclic Aromatic Hydrocarbons: 15 Listings

methylene-bis-o-chloroaniline see 4,4′-Methylenebis(2-chloroaniline)

3-methyl-3H-imidazo[4,5-f]quinolin-2-amine see Heterocyclic Amines (Selected), 2-Amino-3-methylimidazo[4,5-f]quinoline (IQ)

2-methyl-4-[(2-methylphenyl)azo]-benzenamine see o-Aminoazotoluene

2-methyl-5-nitro-lH-imidazole-l-ethanol see Metronidazole

6-[(1-methyl-4-nitro-1H-imidazol-5-yl)thio]-1H-purine see Azathioprine

1-methyl-3-nitro-1-nitrosoguanidine see N-Nitrosamines: 15 Listings, N-Methyl-N′-nitro-N-nitrosoguanidine

4-(methylnitrosamino)-1-(3-pyridyl)-1-butanone see N-Nitrosamines: 15 Listings, 4-(N-Nitrosomethylamino)-1-(3-pyridyl)-1-butanone

2-methyloxirane see Propylene Oxide

methyl-m-phenylene ester see Toluene Diisocyanates

1-methyl-6-phenyl-1H-imidazo[4,5-b]pyridin-2-amine see Heterocyclic Amines (Selected), 2-Amino-1-methyl-6-phenylimidazo[4,5-b]pyridine (PhIP)

methylene chloride see Dichloromethane

4,4′-methylenebis(2-chlorobenzenamine) see 4,4′-Methylenebis(2-chloroaniline)

4,4′-methylenebisbenzenamine see 4,4′-Methylenedianiline and Its Dihydrochloride

4,4′-methylenebisbenzenamine dihydrochloride see 4,4′-Methylenedianiline and Its Dihydrochloride

methylenedianiline dihydrochloride see 4,4′-Methylenedianiline and Its Dihydrochloride

4,4′-methylenedianiline dihydrochloride see 4,4′-Methylenedianiline and Its Dihydrochloride

4-(methylnitrosamino)-1-(3-pyridiyl)-1-butanone see N-Nitrosamines: 15 Listings, 4-(N-Nitrosomethylamino)-1-(3-pyridyl)-1-butanone

methyloxirane see Propylene Oxide

Michler’s base see 4,4′-Methylenebis(N,N-dimethyl)benzenamine

mildly treated mineral oils see Mineral Oils: Untreated and Mildly Treated

mists, strong inorganic acid see Strong Inorganic Acid Mists Containing Sulfuric Acid

monobromoacetic acid see Haloacetic Acids Found as Water Disinfection By-products (Selected)

monochloroacetic acid see Haloacetic Acids Found as Water Disinfection By-products (Selected)

monoiodoacetic acid see Haloacetic Acids Found as Water Disinfection By-products (Selected)

Myleran see 1,4-Butanediol Dimethanesulfonate

N

NDEA see N-Nitrosamines: 15 Listings, N-Nitrosodiethylamine

NEU see N-Nitrosamines: 15 Listings, N-Nitroso-N-ethylurea

Ni see Nickel Compounds and Metallic Nickel

NMU see N-Nitrosamines: 15 Listings, N-Nitroso-N-methylurea

NNK see N-Nitrosamines: 15 Listings, 4-(N-Nitrosomethylamino)-1-(3-pyridyl)-1-butanone

NNN see N-Nitrosamines: 15 Listings, N-Nitrosonornicotine

N-butyl-N-nitroso-l-butamine see N-Nitrosamines: 15 Listings, N-Nitrosodi-n-butylamine

N-(2-chloroethyl)-N′-cyclohexyl-N-nitrosourea see Nitrosourea Chemotherapeutic Agents, 1-(2-Chloroethyl)-3-cyclohexyl-1-nitrosourea

N-(2-chloroethyl)-N-(1-methyl-2-phenoxybenzenemethanamine hydrochloride see Phenoxybenzamine Hydrochloride

N-dibutylnitrosoamine see N-Nitrosamines: 15 Listings, N-Nitrosodi-n-butylamine

N-(4-ethoxyphenyl)acetamide see Phenacetin and Analgesic Mixtures Containing Phenacetin

N-ethyl-N-nitroso-ethanamine see N-Nitrosamines: 15 Listings, N-Nitrosodiethylamine

N-ethyl-N-nitrosourea see N-Nitrosamines: 15 Listings, N-Nitroso-N-ethylurea

N-2-fluorenylacetamide see 2-Acetylaminofluorene

N-fluoren-2-yl-acetamide see 2-Acetylaminofluorene

N-methyl-N-nitroso-ethenylamine see N-Nitrosamines: 15 Listings, N-Nitrosomethylvinylamine

N-methyl-N-nitroso-glycine see N-Nitrosamines: 15 Listings, N-Nitrososarcosine

N-methyl-N-nitroso-N′-nitroguanidine see N-Nitrosamines: 15Listings, N-Methyl-N′-nitro-N-nitrosoguanidine

N-methyl-N-nitrosomethanamine see N-Nitrosamines: 15 Listings, N-Nitrosodimethylamine

N-methyl-N-nitrosourea see N-Nitrosamines: 15 Listings, N-Nitroso-N-methylurea

N-(1-methylethyl)-4-[(2-methylhydrazino)methyl]-benzamide monohydrochloride see Procarbazine and Its Hydrochloride

N-methylvinylnitrosamine see N-Nitrosamines: 15 Listings, N-Nitrosomethylvinylamine

N,N-bis(carboxymethyl)glycine see Nitrilotriacetic Acid

N,N′-bis(2-chloroethyl)-N-nitrosourea see Nitrosourea Chemotherapeutic Agents, Bis(chloroethyl) Nitrosourea

N,N-bis(2-chloroethyl)tetrahydro-2H-1,3,2-oxaphosphorin-2-amine, 2-oxide monohydrate see Cyclophosphamide

N,N-dibutylnitrosoamine see N-Nitrosamines: 15 Listings, N-Nitrosodi-n-butylamine

N,N-diethyldithiocarbamic acid 2-choroallyl ester see Sulfallate

N,N-dimethyl-4-aminoazobenzene see 4-Dimethylaminoazobenzene

N,N-dimethyl-4-(phenylazo)-benzenamine see 4-Dimethylaminoazobenzene

N-Nitroso-N-methylglycine see N-Nitrosamines: 15 Listings, N-Nitrososarcosine

N-nitroso-N-propyl-1-propanamine see N-Nitrosamines: 15 Listings, N-Nitrosodi-n-propylamine

N-nitrosodipropylamine see N-Nitrosamines: 15 Listings, N-Nitrosodi-n-propylamine

N-nitrosoethylurea see N-Nitrosamines: 15 Listings, N-Nitroso-N-ethylurea

N-nitrosomethylurea see N-Nitrosamines: 15 Listings, N-Nitroso-N-methylurea

N-nitrosophenylhydroxylamine, ethanolamine salt see Cupferron

naphtho(1,2,3,4-def)chrysene see Polycyclic Aromatic Hydrocarbons: 15 Listings, Dibenzo[a,e]pyrene

β-naphthylamine see 2-Naphthylamine

beta-naphthylamine see 2-Naphthylamine

neutrons see Ionizing Radiation

nickelocene see Nickel Compounds and Metallic Nickel

niclofen see Nitrofen

2-nitroanisole see o-Nitroanisole

nitrochlor see Nitrofen

6-nitrochrysene see Nitroarenes (Selected)

nitrogen mustard see Nitrogen Mustard Hydrochloride

1-nitropyrene see Nitroarenes (Selected)

nitropyrene see Nitroarenes (Selected)

4-nitropyrene see Nitroarenes (Selected)

nitrosodibutylamine see N-Nitrosamines: 15 Listings, N-Nitrosodi-n-butylamine

2,2′-(nitrosoimino)bis[ethanol] see N-Nitrosamines: 15 Listings, N-Nitrosodiethanolamine

4-nitrosomorpholine see N-Nitrosamines: 15 Listings, N-Nitrosomorpholine

1-nitroso-piperidine see N-Nitrosamines: 15 Listings, N-Nitrosopiperidine

3-(1-nitroso-2-pyrrolidinyl)pyridine see N-Nitrosamines: 15 Listings, N-Nitrosonornicotine

1-nitrosopyrrolidine see N-Nitrosamines: 15 Listings, N-Nitrosopyrrolidine

2-nitrotoluene see o-Nitrotoluene

norethindrone see Norethisterone

O

o-o′-DDT see Dichlorodiphenyltrichloroethane

o-p′-DDT see Dichlorodiphenyltrichloroethane

o-aminoanisole see o-Anisidine and Its Hydrochloride

o-dianisidine see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine, Dyes Metabolized to 3,3′-Dimethoxybenzidine

o-tolidine see 3,3′-Dimethylbenzidine and Dyes Metabolized to 3,3′-Dimethylbenzidine, Dyes Metabolized to 3,3′-Dimethylbenzidine

octabromobiphenyl see Polybrominated Biphenyls

Oleum see Strong Inorganic Acid Mists Containing Sulfuric Acid

orange 16 see 3,3′-Dimethoxybenzidine and Dyes Metabolized to 3,3′-Dimethoxybenzidine

orthoarsenic acid see Arsenic and Inorganic Compounds

Owens-Corning FG insulation fiberglass with binder see Certain Glass Wool Fibers (Inhalable)

Owens-Corning FM series air filter media see Certain Glass Wool Fibers (Inhalable)

Owens-Corning glass wool see Certain Glass Wool Fibers (Inhalable)

1,2-oxathiolane, 2,2-dioxide see 1,3-Propane Sultone

2-oxetanone see β-Propiolactone

oxirane see Ethylene Oxide

oxiranemethanol see Glycidol

3-oxiranyl-7-oxabicyclo[4.1.0]heptane see 4-Vinyl-1-cyclohexene Diepoxide

4,4′-oxybisbenzenamine see 4,4′-Oxydianiline

P

p-aminobiphenyl see 4-Aminobiphenyl

p-aminodiphenyl see 4-Aminobiphenyl

p-dichlorobenzene see 1,4-Dichlorobenzene

p-dimethylaminoazobenzene see 4-Dimethylaminoazobenzene

p-rosaniline hydrochloride see Basic Red 9 Monohydride

p,p′-DDT see Dichlorodiphenyltrichloroethane

p,p′-tetramethyldiaminodiphenylmethane see 4,4′-Methylenebis(N,N-dimethyl)benzenamine

PAHs see Polycyclic Aromatic Hydrocarbons: 15 Listings

Pb see lead

PBBs see Polybrominated Biphenyls

PCBs see Polychlorinated Biphenyls

PCDD see 2,3,7,8-Tetrachlorodibenzo-p-dioxin

PCP see Pentachlorophenol and By-products of Its Synthesis

PhIP see Heterocyclic Amines (Selected), 2-Amino-1-methyl-6-phenylimidazo-[4,5-b]pyridine

PROP see Propylthiouracil

PUVA see Methoxsalen with Ultraviolet A Therapy

p-rosaniline hydrochloride see Basic Red 9 Monohydride

para-aminodiphenyl see 4-Aminobiphenyl

para-dimethylaminoazobenzene see 4-Dimethylaminoazobenzene

paraffins, chlorinated see Chlorinated Paraffins

paraformaldehyde see Formaldehyde

pararosaniline hydrochloride see Basic Red 9 Monohydrochloride

passive smoke see Tobacco-Related Exposures, Environmental Tobacco Smoke

pentabromobiphenyl see Polybrominated Biphenyls

pentachlorobiphenyl see Polychlorinated Biphenyls

perc see Tetrachloroethylene

perchloroethylene see Tetrachloroethylene

petroleum see Mineral Oils: Untreated and Mildly Treated

L-phenylalanine, N-[(5-chloro-3,4-dihydro-8-hydroxy-3-methyl-1-oxo-1H-2-benzopyran-7-yl)-carbonyl]-, (R)- see Ochratoxin A

3-phenylazo-2,6-diaminopyridine hydrochloride see Phenazopyridine Hydrochloride

3-(phenylazo)-2,6-pyridinediamine monohydrochloride see Phenazopyridine Hydrochloride

2,2′-[phenylenebis(oxymethylene)]bisoxirane see Diglycidyl Resorcinol Ether

phenyloxirane see Styrene-7,8-oxide

1,1′,1′′-phosphinothioylidynetrisaziridine see Thiotepa

Phthalate esters see Di(2-ethylhexyl) Phthalate

pipe smoking see Tobacco-Related Exposures

piperazine estrone sulfate see Estrogens, Steroidal

platinum, diamminedichloro-, (SP-4-2)- see Cisplatin

polychlorinated camphenes see Toxaphene

polychlorocamphene see Toxaphene

polychlorophenols see 2,4,6-Trichlorophenol

polynuclear aromatic hydrocarbons see Polycyclic Aromatic Hydrocarbons: 15 Listings

potassium arsenate see Arsenic and Inorganic Arsenic Compounds

potassium arsenite see Arsenic and Inorganic Arsenic Compounds

potassium chromate see Chromium Hexavalent Compounds

potassium dichromate see Chromium Hexavalent Compounds

pregn-4-ene-3,20-dione see Progesterone

progestin see Progesterone

propane sultone see 1,3-Propane Sultone

2-propenamide see Acrylamide

2-propenenitrile see Acrylonitrile

5-(2-propenyl)-1,3-benzodioxole see Safrole

n-propyl bromide see 1-Bromopropane

6-propyl-2-thiouracil see Propylthiouracil

6-n-propylthiouracil see Propylthiouracil

propylenimine see 2-Methylaziridine

psoralen see Methoxsalen with Ultraviolet A Therapy

pyridium see Phenazopyridine Hydrochloride

Q

quartz see Silica, Crystalline (Respirable Size)

R

Rn see Ionizing Radiation, Radon

radiation, ionizing see Ionizing Radiation

radon see Ionizing Radiation, Radon

refractory ceramic fibers see Ceramic Fibers (Respirable Size)

resorcinol diglycidyl ether see Diglycidyl Resorcinol Ether

respirable crystalline silica see Silica, Crystalline (Respirable Size)

p-rosaniline hydrochloride see Basic Red 9 Monohydride

S

SCCP see Chlorinated Parafins

sawdust see Wood Dust

Schleicher and Schuell (S&S 106) glass wool fibers see Certain Glass Wool Fibers (Inhalable)

secondhand smoke see Tobacco-Related Exposures, Environmental Tobacco Smoke

Selsun see Selenium Sulﬁde

semustine see Nitrosourea Chemotherapeutic Agents, 1-(2-Chloroethyl)-3-(4-methylcyclohexyl)-1-nitrosourea

short-chain chlorinated paraffins see Chorinated Paraffins

sidestream smoke see Tobacco-Related Exposures, Environmental Tobacco Smoke

sintered carbides see Cobalt-Related Exposures, Cobalt–Tungsten Carbide: Powders and Hard Metals

smokeless tobacco see Tobacco-Related Exposures

snuff see Tobacco-Related Exposures, Smokeless Tobacco

sodium arsenate see Arsenic and Inorganic Arsenic Compounds

sodium arsenite see Arsenic and Inorganic Arsenic Compounds

sodium chromate see Chromium Hexavalent Compounds

sodium dichromate see Chromium Hexavalent Compounds

sodium equilin sulfate see Estrogens, Steroidal

sodium estrone sulfate see Estrogens, Steroidal

solar radiation see Ultraviolet Radiation Related Exposures

solvent blue 18 (C.I.) see Disperse Blue 1

special-purpose glass fibers see Certain Glass Wool Fibers (Inhalable)

spirits see Alcoholic Beverage Consumption

steroidal estrogens see Estrogens, Steroidal

stilbestrol see Diethylstilbestrol

strontium chromate see Chromium Hexavalent Compounds

styrene oxide see Styrene-7,8-oxide

sulfur mustard see Mustard Gas

sulfuric acid see Strong Inorganic Acid Mists Containing Sulfuric Acid

sunbeds see Ultraviolet Radiation Related Exposures, Sunlamps or Sunbeds, Exposure to

sunlamps see Ultraviolet Radiation Related Exposures

synthetic mineral fibers see Ceramic Fibers (Respirable Size) and Certain Glass Wool Fibers (Inhalable)

synthetic vitreous fibers see Certain Glass Wool Fibers (Inhalable)

T

TCDD see 2,3,7,8-Tetrachlorodibenzo-p-dioxin

2,3,7,8-TCDD see 2,3,7,8-Tetrachlorodibenzo-p-dioxin

TCE see Trichloroethylene

TDI see Toluene Diisocyanates

TEPA see Thiotepa

TFE see Tetrafluoroethylene

TRIS see Tris(2,3-dibromopropyl) Phosphate

Telone II see 1,3-Dichloropropene (Technical Grade)

Tempstran code 100/475 glass fibers see Certain Glass Wool Fibers (Inhalable)

2-tert-butyl-4-hydroxyanisole (2-BHA) see Butylated Hydroxyanisole

3-tert-butyl-4-hydroxyanisole (3-BHA) see Butylated Hydroxyanisole

1,4,5,8-tetraamino-9,10-anthracenedione see Disperse Blue 1

1,4,5,8-tetraaminoanthraquinone see Disperse Blue 1

tetrachlorobiphenyl see Polychlorinated Biphenyls

tetrachloroethene see Tetrachloroethylene

tetrachloromethane see Carbon Tetrachloride

tetraethyl lead see Lead and Lead Compounds

tetrafluoroethene see Tetrafluoroethylene

tetramethyl lead see Lead and Lead Compounds

p,p′-tetramethyldiaminodiphenylmethane see 4,4′-Methylenebis(N,N-Dimethyl)benzenamine

4,4′-thiobisbenzenamine see 4,4′-Thiodianiline

1,1′-thiobis(2-chloroethane) see Mustard Gas

thiodianiline see 4,4′-Thiodianiline

thorium dioxide see Ionizing Radiation

thorium oxide see Ionizing Radiation, Thorium Dioxide

thoron see Ionizing Radiation, Radon

Thorotrast see Ionizing Radiation, Thorium Dioxide

tobacco smoking see Tobacco-Related Exposures

o-tolidine see 3,3′-Dimethylbenzidine and Dyes Metabolized to 3,3′-Dimethylbenzidine, Dyes Metabolized to 3,3′-Dimethylbenzidine

2,4-toluene diisocyanate see Toluene Diisocyanates

2,6-toluene diisocyanate see Toluene Diisocyanates

toluenediamine see 2,4-Diaminotoluene

tolylene diisocyanate see Toluene Diisocyanates

trans-1,3-dichloropropene see 1,3-Dichloropropene (Technical Grade)

tremolite see Asbestos

tribromoacetic acid see Haloacetic Acids Found as Water Disinfection By-products (Selected)

trichloroacetic acid see Haloacetic Acids Found as Water Disinfection By-products (Selected)

1,1,1-trichloro-2,2-bis(p-chlorophenyl) ethane see Dichlorodiphenyltrichloroethane

trichloroethene see Trichloroethylene

1,1,2-trichloroethene see Trichloroethylene

trichloromethane see Chloroform

1-(trichloromethyl)benzene see Benzotrichloride

α,α,α-trichlorotoluene see Benzotrichloride

tridymite see Silica, Crystalline (Respirable Size)

triethylenethiophosphoramide see Thiotepa

trimethylene methanesulfonate see 1,4-Butanediol Dimethanesulfonate

trioxane see Formaldehyde

tris(1-aziridinyl)phosphine sulfide see Thiotepa

trypan blue see 3,3′-Dimethylbenzidine and Dyes Metabolized to 3,3′-Dimethylbenzidine, Dyes Metabolized to 3,3′-Dimethylbenzidine

tungsten carbides see Cobalt-Related Exposures, Cobalt–Tungsten Carbide: Powders and Hard Metals

U

UMDH see 1,1-Dimethylhydrazine

UVA see Ultraviolet Radiation Related Exposures

UVB see Ultraviolet Radiation Related Exposures

UVC see Ultraviolet Radiation Related Exposures

UVR see Ultraviolet Radiation Related Exposures

unsymmetrical dimethylhydrazine see 1,1-Dimethylhydrazine

untreated mineral oils see Mineral Oils: Untreated and Mildly Treated

urethan see Urethane

V

Vidaza see Azacitidine

4-vinylcyclohexene diepoxide see 4-Vinyl-1-cyclohexene Diepoxide

vinylcyclohexene dioxide see 4-Vinyl-1-cyclohexene Diepoxide

vitreous fibers see Certain Glass Wool Fibers (Inhalable)

W

WC/Co see Cobalt-Related Exposures, Cobalt-Tungsten Carbide: Powders and Hard Metals

wine see Alcoholic Beverage Consumption

X

xanthotoxin see Methoxsalen with Ultraviolet A Therapy

X-radiation see Ionizing Radiation

X-rays see Ionizing Radiation, X-Radiation and Gamma Radiation

Y

yohimban-16-carboxylic acid, 11,17-dimethoxy-18-[(3,4,5-trimethoxybenzoyl)oxy]-, methyl ester, (3β,16β,17α,18β,20α)- see Reserpine

Z

(Z)-1,3-dichloropropene see 1,3-Dichloropropene (Technical Grade)

(Z)-2-[4-(1,2-diphenylbut-1-enyl)phenoxy]-N,N-dimethylethanamine see Tamoxifen

Zanosar see Streptozocin

zeolites see Erionite

zinc beryllium silicate see Beryllium and Beryllium Compounds

zinc chromates see Chromium Hexavalent Compounds

zinc yellow see Chromium Hexavalent Compounds