# Appendix E Chemicals Nominated to the NTP for In-Depth Toxicological Evaluation

A searchable database of substances nominated to the NTP for toxicological testing is available on the NTP website at http://ntp.niehs.nih.gov/go/nom-search. The available information includes the substance nominated and the nomination date, source, rationale, and status. If NTP testing has been conducted, a link is provided to the results and status information. Nominations can be searched by substance name, Chemical Abstract Service Registry Number (CASRN) or keyword.

The Management Status Report (http://ntp.niehs.nih.gov/go/MSR-index) gives the status of substances selected for study using standard 2-week, 13-week, and/or 2-year toxicology and carcinogenicity protocols. Abstracts for all published NTP long-term carcinogenicity technical reports and short-term toxicity study reports are available electronically on the NTP Web site. To view the abstracts or download full reports, visit http://ntp.niehs.nih.gov.

For additional information about NTP studies, contact Central Data Management, Mail Drop K2-05, NIEHS, P.O. Box 12233, Research Triangle Park, NC 27709 (phone: 919-541-3419; e-mail: CDM@niehs.nih.gov).