# Appendix D 15th RoC and Monographs – Collaborators and Contributors

## D.1 National Institute of Environmental Health Sciences (NIEHS), National Toxicology Program (NTP) Members

- Rick Woychik, Ph.D.
  Director, NIEHS and NTP
- Brian R. Berridge, D.V.M., Ph.D., D.A.C.V.P.
  Associate Director, NTP
  Scientific Director, Division of the NTP (DNTP)
- Ruth Lunn, Dr.P.H.
  Director, Office of the Report on Carcinogens (ORoC)
- Gloria Jahnke, D.V.M., D.A.B.T.
  Health Scientist, ORoC
- Suril S. Mehta, Dr.P.H.
  Health Scientist, ORoC
- H.S. Amy Wang, Ph.D.
  Health Scientist, ORoC
- John R. Bucher, Ph.D., D.A.B.T.
  Senior Scientist, DNTP
- Mary S. Wolfe, Ph.D.
  Deputy Program Director for Policy, DNTP
  Director, NTP Office of Liaison, Policy, and Review
- Linda Birnbaum, Ph.D., D.A.B.T., A.T.S.
  Former Director, NIEHS and NTP (through 3 Oct 2019)

## D.2 Contract Support Staff for the RoC

- Susan Dakin, Ph.D.
  Technical and Scientific Writing and Editing
  Independent Consultant
  Durham, NC
- Sanford Garner, Ph.D.
  Project Manager, Integrated Laboratory Systems (ILS), Inc.
- Whitney Arroyave, Ph.D.
  Epidemiologist, ILS, Inc.
- Stanley Atwood, M.S., D.A.B.T.
  Toxicologist, ILS, Inc.
- Ella Darden, B.S.
  Administrative Support Specialist, ILS, Inc.
- Andrew Ewens, Ph.D., D.A.B.T.
  Toxicologist, ILS, Inc.
- Jessica Geter, M.S.L.S.
  Information Specialist, ILS, Inc.
- Lara Handler, M.S.L.S.
  Information Specialist, ILS, Inc.
- Alton Peters, M.S.
  Environmental Scientist, ILS, Inc.
- Tracy Saunders, B.S.
  Administrative Support Specialist, ILS, Inc.
- Pamela Schwingl, Ph.D.
  Epidemiologist, ILS, Inc.

## D.3 Participants in Preparation and Review of RoC Monographs

### D.3.1 Antimony Trioxide

#### D.3.1.1 Provided Technical Input or Review

- Melanie C. Buser, M.P.H.
  Agency for Toxic Substances and Disease Registry
  Centers for Disease Control and Prevention
- Stephen S. Ferguson, Ph.D.
  NTP Biomolecular Screening Branch
- Gordon P. Flake, M.D. (Deceased July 30, 2018)
  NTP Cellular and Molecular Pathology Branch
- Kristina M. Hatlelid, Ph.D., M.P.H.
  Directorate for Health Sciences,
  U.S. Consumer Product Safety Commission
- Michelle J. Hooth, Ph.D.
  NTP Program Operations Branch
- Jui-Hua Hsieh, Ph.D.
  NTP Biomolecular Screening Branch
- B. Alex Merrick, Ph.D.
  NTP Biomolecular Screening Branch
- Daniel L. Morgan, Ph.D.
  NTP Toxicology Branch
- Arun K. R. Pandiri, B.V.Sc, M.S., Ph.D.
  NTP Cellular and Molecular Pathology Branch
- Linda M. Sargent, Ph.D.
  Health Effects Laboratory Division, Centers for Disease Control and Prevention
- Matthew D. Stout, Ph.D.
  NTP Program Operations Branch
- Kyla W. Taylor, Ph.D.
  NTP Office of Health Assessment and Translation
- Erik J. Tokar, Ph.D.
  NTP Laboratory Branch
- Joanne Trgovcich, Ph.D.
  Senior Technical Specialist, ICF, Inc.
- Suramya Waidyanatha, Ph.D.
  NTP Program Operations Branch
- Yin-tak Woo, Ph.D.
  Office of Chemical Safety and Pollution Prevention
  U.S. Environmental Protection Agency

#### D.3.1.2 Peer Review Panel

- Rebecca Fry, Ph.D. (Chair)
  Gillings School of Global Public Health,
  University of North Carolina at Chapel Hill
  Chapel Hill, NC
- Richard Peterson II, D.V.M., Ph.D., D.A.C.V.P.
  AbbVie
  Libertyville, IL
- Elaine Symanski, Ph.D.
  The University of Texas Health Science Center at Houston
  Houston, TX
- Elizabeth Ward, Ph.D.
  American Cancer Society
  Asheville, NC
- John Wise, Sr., Ph.D.
  University of Louisville
  Louisville, KY
- Hao Zhu, Ph.D.
  The Rutgers Center for Computational and Integrative Biology, Rutgers University
  Camden, NJ

### D.3.2 Haloacetic Acids Found as Water Disinfection By-Products

#### D.3.2.1 Provided Technical Input or Review

- Scott Auerbach, Ph.D.
  NTP Biomolecular Screening Branch
- Windy A. Boyd, Ph.D.
  NTP Office of Health Assessment and Translation
- Michael Devito, Ph.D.
  NTP Laboratory Branch
- Stephen S. Ferguson, Ph.D.
  NTP Biomolecular Screening Branch
- Michelle J. Hooth, Ph.D.
  NTP Program Operations Branch
- Scott A. Masten, Ph.D., D.A.B.T.
  NTP Office of Nomination and Selection
- Arun K.R. Pandiri, B.V.Sc, M.S., Ph.D.
  NTP Cellular and Molecular Pathology Branch
- Grace Patlewicz, Ph.D.
  Center for Computational Toxicology
  U.S. Environmental Protection Agency
- Kristen Ryan, Ph.D.
  NTP Toxicology Branch
- Jane Ellen Simmons, Ph.D.
  Pharmacokinetics Branch
  U.S. Environmental Protection Agency
- Suramya Waidyanatha, Ph.D.
  NTP Program Operations Branch
- Nigel J. Walker, Ph.D., D.A.B.T.
  NTP Toxicology Branch
- Vickie R. Walker, B.S.
  NTP Toxicology Branch

#### D.3.2.2 External Technical Advisors

- Ron Melnick, Ph.D.
  Ron Melnick Consulting, LLC
  North Logan, UT
- Michael Plewa, Ph.D.
  University of Illinois at Urbana–Champaign
  Urbana, IL
- Susan Richardson, Ph.D.
  University of South Carolina
  Columbia, SC

#### D.3.2.3 Peer Review Panel

- Weihsueh Chiu, Ph.D. (Chair)
  Texas A&M University
  College Station, TX
- Mathias Attene Ramos, Ph.D.
  George Washington University
  Washington, DC
- Julia H. Carter, Ph.D.
  Wood Hudson Cancer Research Laboratory
  Newport, KY
- Lawrence H. Lash, Ph.D.
  Wayne State University School of Medicine
  Detroit, MI
- Shahid Parvez, Ph.D.
  Indiana University–Purdue University
  Indianapolis, IN
- Stephen M. Roberts, Ph.D.
  University of Florida
  Gainesville, FL
- Consolato Sergi, M.D., Ph.D., M.P.H, F.R.C.P.C.
  University of Alberta
  Edmonton, Alberta, Canada
- Susan C. Tilton, Ph.D.
  Oregon State University
  Corvallis, OR

### D.3.3 Helicobacter pylori (Chronic Infection)

#### D.3.3.1 Provided Technical Input or Review

- Brandy Beverly, Ph.D.
  NTP Office of Health Assessment and Translation
- Michelle J. Hooth, Ph.D.
  NTP Program Operations Branch
- David Malarkey, Ph.D.
  NTP CMPB
- Scott A. Masten, Ph.D., D.A.B.T.
  NTP Office of Nomination and Selection
- Charles Rabkin, M.D.
  Division of Cancer Epidemiology and Genetics,
  National Cancer Institute

#### D.3.3.2 Peer Reviewers (by Letter)

- Rolando Herrero, M.D., Ph.D.
  International Agency for Research on Cancer
  Lyon, France
- Julie Parsonnet, M.D.
  Stanford University Medical Center
  Stanford, CA
- Traci L. Testerman, Ph.D.
  University of South Carolina School of Medicine
  Columbia, SC