# Appendix C Substances Reviewed but Not Recommended for Listing in the Report on Carcinogens

The following table contains a record of nominations that were formally considered for listing by the NTP and, after evaluation by the Report on Carcinogens review groups, were recommended not to be listed in the Report on Carcinogens.

Table C-1 Substances Reviewed but Not Recommended for Listing in the Report on Carcinogens

Substance Name/ CAS Number | RoC Edition/ Review Date^1^ | Reason for Not Listing | Review Document^2^
Methyl tert-butyl ether (MTBE) 1634-04-4 | Ninth RoC 1998 | Rodent cancer data were not sufficient. | https://ntp.niehs.nih.gov/ntp/newhomeroc/other_background/mtbe1_508.pdf
Nickel alloys | Tenth RoC 2000 | Human data were inadequate, and rodent cancer data were not sufficient. | https://ntp.niehs.nih.gov/ntp/newhomeroc/roc10/ni_no_appendices_508.pdf
Diethanolamine 111-42-2 | Eleventh RoC 2002 | Rodent cancer data not sufficient | https://ntp.niehs.nih.gov/ntp/newhomeroc/roc11/deapub_no_appendices_508.pdf
Monochloroacetic Acid 79-11-8 | Fifteenth RoC 2018 | Rodent cancer data were not sufficient. | https://ntp.niehs.nih.gov/go/HAAs
Trichloroacetic Acid 76-03-9 | Fifteenth RoC 2018 | Rodent cancer data were not sufficient. | https://ntp.niehs.nih.gov/go/HAAs
Light at Night | Fifteenth RoC 2020 | It is uncertain whether the exposure circumstance meets the definition of “substance.” | https://ntp.niehs.nih.gov/go/NSW_LAN
Night Shift Work | Fifteenth RoC 2020 | It is uncertain whether the exposure circumstance meets the definition of “substance.” | https://ntp.niehs.nih.gov/go/NSW_LAN

^1^ Final background document or monograph.

^2^ URL for the document or for the website from which the document can be accessed.