# Appendix B Substances Delisted from the Report on Carcinogens

The agents, substances, mixtures, or exposure circumstances contained in this appendix were previously listed in the Report on Carcinogens (RoC) as either known or reasonably anticipated to be human carcinogens. For substances removed from the RoC prior to the 1996 establishment of a formal review procedure for delisting substances from the RoC, Table B-1 below shows the reason for delisting. The table indicates the last edition of the RoC in which these substances appeared, to which reference can be made for all information available.

For each substance removed from the RoC as a result of a formal review for delisting (from the eighth edition forward), a profile is provided following the table, which summarizes the review for delisting, including the relevant information and the issues identified by the scientific review groups that led to the substance’s delisting.

Table B-1 Substances Delisted from the Report on Carcinogens

Substance Name | CAS Number | Last Listing | Reason for Delisting
Chloramphenicol | 56-75-7 | known First RoC (1980) | Human data considered inadequate
Aramite | 140-57-8 | reasonably anticipated Fourth RoC (1985) | No U.S. residents exposed
N,N-Bis(2-chloroethyl)-2-naphthylamine (chlornaphazine) | 494-03-1 | known Fourth RoC (1985) | No U.S. residents exposed
Cycasin | 14901-08-7 | reasonably anticipated Fourth RoC (1985) | No U.S. residents exposed
Methyl iodide | 78-88-4 | reasonably anticipated Fourth RoC (1985) | Reevaluated by IARC; evidence now considered equivocal
5-Nitro-o-anisidine | 99-59-2 | reasonably anticipated Fifth RoC (1989) | Insufficient evidence of carcinogenicity
p-Nitrosodiphenylamine | 156-10-5 | reasonably anticipated Fifth RoC (1989) | Insufficient evidence of carcinogenicity
Ethyl acrylate | 140-88-5 | reasonably anticipated Eighth RoC (1998) | See following profile
Saccharin | 81-07-2 | reasonably anticipated Eighth RoC (1998) | See following profile

## B.1 Report on Carcinogens Review Group Actions on the Nomination of Ethyl Acrylate for Delisting from the Report on Carcinogens

Summary of data contained in the Ethyl Acrylate Background Document (December 1998).

### B.1.1 Ethyl Acrylate

CAS No. 140-88-5

Ethyl acrylate is used in various industries as an intermediate in the production of emulsion-based polymers which are then used in paint formulations, industrial coatings, and latex products. It is also used as a synthetic flavoring substance and fragrance adjuvant in consumer products. Human exposure to ethyl acrylate occurs mostly through inhalation of ethyl acrylate vapors, but it may also result from skin contact or ingestion as a food additive or from drinking of contaminated water. The Report on Carcinogens review groups considered the data underlying the nomination to remove ethyl acrylate from the Report on Carcinogens, where it has been listed as reasonably anticipated to be a human carcinogen since 1989. The basis for this listing was a gavage study that resulted in dose-related benign and malignant forestomach neoplasms in rats and mice. The Basic Acrylic Monomer Manufacturers, Inc. (BAMM), submitted a nomination to remove ethyl acrylate from the Report on Carcinogens based upon the following information: (1) negative tumorigenicity results from chronic-exposure studies using routes other than gavage in corn oil, (2) research results suggesting that the forestomach carcinogenicity observed in the gavage studies was secondary to a site-specific and concentration-dependent irritating effect of ethyl acrylate, and (3) the fact that significant human exposure to ethyl acrylate monomer is unlikely in light of current manufacturing practices and patterns of usage (see Human Exposure and Cancer Studies in Humans, below).

The majority opinion of the Report on Carcinogens review groups was to recommend that ethyl acrylate be removed from the Report on Carcinogens. This opinion was based on the facts that (1) the forestomach tumors induced in animal studies were seen only when ethyl acrylate was administered by gavage at high concentrations that induced marked local irritation and cellular proliferation, (2) animal studies using other routes of administration, including inhalation, gave negative results, and (3) significant chronic human oral exposure to high concentrations of ethyl acrylate monomer is unlikely. Therefore, ethyl acrylate does not meet the criteria to be listed in the Report on Carcinogens as reasonably anticipated to be a human carcinogen

#### B.1.1.1 Summary of Available Carcinogenicity Data and Other Relevant Information

##### B.1.1.1.1 Cancer Studies in Experimental Animals

Although mutagenic in some in vitro tests, ethyl acrylate is not genotoxic under in vivo physiological conditions, perhaps because of its rapid metabolism to acrylic acid and ethanol by carboxyesterases and detoxification through binding to non-protein sulfhydryls. Target tissue toxicity in the form of irritation was observed in the skin in a lifetime mouse skin-painting study, in the nasal olfactory mucosa in 27-month inhalation studies in rats and mice, and in the forestomach in two-year corn-oil gavage studies in rats and mice. Only bodyweight reduction was observed in a two-year study of exposure via drinking water in rats. The forestomach carcinogenicity observed in the corn-oil gavage studies was the only treatment-related tumorigenic response in the various animal studies. The irritation, hyperplasia and tumor responses in the forestomach were related more to target-tissue concentration of ethyl acrylate than to delivered dose in the chronic gavage study. Based upon stop-exposure studies, gavage doses of ethyl acrylate in corn oil sufficient to induce sustained mucosal hyperplasia in the forestomach must be administered for longer than six months to induce forestomach neoplasia.

##### B.1.1.1.2 Human Exposure and Cancer Studies in Humans

Prolonged consumer exposure to high levels of ethyl acrylate monomer by the oral route is unlikely. Potentially significant exposures would most likely occur in an occupational setting where the routes of exposure would be dermal or by inhalation. Ethyl acrylate has a strong acrid odor (odor threshold ~0.5 ppb) and is a known irritant to the skin, eyes, and mucous membranes, making it unlikely that humans would be chronically exposed to high concentrations. Data provided in the BAMM nomination on worker exposure showed occupational exposure well below the threshold limit value (TLV = 5 ppm for an eight-hour time-weighted average) and the short-term exposure limit (STEL = 15 ppm), although exposure of painters in an unventilated room has been reported to be as high as 8 ppm in the painter’s breathing zone.

An epidemiology study reported on mortality from cancer of the colon and rectum in three separate cohorts of workers from two plants manufacturing and polymerizing acrylate monomers. Workers were exposed to ethyl acrylate and methyl methacrylate monomer between 1933 and 1982. Risks for both types of cancer were associated with exposure in the earliest cohort, although the rectal cancer results are imprecise because of the small number of cases involved. The greatest relative risk was found in workers with the highest level of exposure and a 20-year latency. The other two cohorts, with later dates of hire, showed no excess risk, but very few cases were available for observation. This study, by itself, can neither establish nor rule out a causal relationship of ethyl acrylate with cancer.

#### B.1.1.2 Action on Nomination

Ethyl acrylate will be removed from the Report on Carcinogens because the relevant data are not sufficient to meet the current criteria to list this chemical as reasonably anticipated to be a human carcinogen. This is based on the fact that the forestomach tumors induced in animal studies were seen only when the chemical was administered by gavage at high concentrations of ethyl acrylate, that induced marked local irritation and cellular proliferation, and because significant chronic human exposure to high concentrations of ethyl acrylate monomer is unlikely.

## B.2 Report on Carcinogens Review Group Actions on the Nomination of Saccharin for Delisting from the Report on Carcinogens

Summary of data contained in the Saccharin Background Document (October 1997).

### B.2.1 Saccharin

CAS No. 81-07-2

Saccharin and its sodium and potassium salts have been produced commercially in the United States for over 80 years. Saccharin is primarily used as a non-nutritive sweetening agent. Potential exposure to saccharin occurs through the consumption of dietetic foods and drinks and the use of some personal hygiene products. Potential exposure to saccharin also occurs in the workplace, specifically in occupations, industries, or facilities that produce and deal with saccharin and its salts. The Report on Carcinogens review groups considered the data underlying the nomination to remove saccharin from the Report on Carcinogens where it has been listed as reasonably anticipated to be a human carcinogen since 1981. The basis for this listing was sufficient evidence of carcinogenicity in experimental animals. The Calorie Control Council submitted a nomination to the NTP to consider removing saccharin from the Report on Carcinogens based upon mechanistic data related to development of urinary-bladder cancers in rats (see Studies on Mechanisms of Carcinogenesis, below).

The majority opinion of the review groups was to recommend that saccharin be removed from the Report on Carcinogens. There is evidence for the carcinogenicity of saccharin in rats, but less convincing evidence in mice. Studies indicate that the observed urinarybladder cancers in rats are related to the physiology of the rat urinary system, including urinary pH, osmolality, volume, the presence of precipitate, and urothelial damage with attendant hyperplasia following consumption of diets containing sodium saccharin at concentrations of 3% or higher, with inconsistent findings at lower dietary concentrations. The factors thought to contribute to tumor induction by sodium saccharin in rats would not be expected to occur in humans. The mouse data are inconsistent and require verification by additional studies. Results of several epidemiology studies indicate no clear association between saccharin consumption and urinary-bladder cancer. Although it is impossible to conclude with absolute certainty that it poses no threat to human health, sodium saccharin is not reasonably anticipated to be a human carcinogen under conditions of general usage as an artificial sweetener.

#### B.2.1.1 Summary of Available Carcinogenicity Data and Other Relevant Information

##### B.2.1.1.1 Cancer Studies in Experimental Animals

In four studies of up to 30 months’ duration, sodium saccharin was carcinogenic in Charles River CD and Sprague-Dawley male rats, as evidenced by a dose-related increased incidence of benign or malignant urinary-bladder neoplasms at dietary concentrations greater than 1% (Arnold et al. 1980; Schoenig et al. 1985; Taylor et al. 1980; Tisdel et al. 1974). Non-statistically significant increases in urinary-bladder cancer also were seen in saccharin-exposed female rats in studies showing a positive effect in males (Arnold et al. 1980; Taylor et al. 1980). Furthermore, several initiation/promotion studies in different rat strains showed a reduced latency and/ or increased incidence of similar urinary-bladder cancers in male and female rats fed sodium saccharin after treatment with various urinary-bladder tumor initiators (e.g., Cohen et al. 1979; Fukushima et al. 1990; Hicks and Chowaniec 1977; Nakanishi et al. 1980; West 1986). Several additional rat studies in which sodium saccharin was administered either in the diet or in drinking water gave negative results for tumorigenicity (Chowaniec and Hicks 1979; Fitzhugh et al. 1951; Hooson et al. 1980; Lessel 1971; Schmähl 1973; Schmähl and Habs 1984).

Three mouse studies reported carcinogenicity following exposure to saccharin. Two of these studies involved surgical implantation of saccharin-containing cholesterol pellets into the urinary bladders and resulted in development of malignant urothelial neoplasms (Allen et al. 1957; Bryan et al. 1970). In the third study, dietary exposure to sodium saccharin resulted in increased incidences of malignant thyroid-gland neoplasms (Prasad and Rai 1986). Although the data from studies in mice cannot be discounted, some of these studies had methodological flaws, provided limited information, did not show a dose-response relationship, or had unexpected outcomes that may be species- or strain-specific, and should be verified by additional studies. The results of four studies in mice were judged negative for tumorigenesis (Frederick et al. 1989; Homburger 1978; Kroes et al. 1977; Roe et al. 1970), as were limited studies in nonhuman primates (Cohen et al. 1996; McChesney et al. 1977; Sieber and Adamson 1978; Thorgeirsson et al. 1994) and a single hamster study (Althoff et al. 1975).

##### B.2.1.1.2 Cancer Studies in Humans

Most of the relevant human epidemiology studies examined associations between urinary-bladder cancer and artificial sweeteners, rather than saccharin per se. The time-trend data for urinary-bladder cancer showed no clear indication that the increased use of saccharin or artificial sweeteners commencing in the 1940s was associated with a general increase in urinary-bladder cancer when confounding factors, chiefly smoking, were controlled for. Risks of urinary-bladder cancer in diabetics, who presumably consume greater amounts of artificial sweeteners than the general population, were no greater than risks in the general population (Armstrong and Doll 1975). Based upon several case-control studies, there was no overall association between use of artificial sweeteners and urinary-bladder cancer (reviewed by IARC 1980; 1987b; JECFA 1993). However, an association between use of artificial sweeteners and urinary-bladder cancer could not be ruled out in some case-control subgroups, albeit involving small numbers (Cartwright et al. 1981; Hoover and Hartge Strasser 1980; Howe et al. 1980; Mommsen et al. 1983; Morrison et al. 1982). Taken together, the available epidemiology data show no consistent evidence that saccharin is associated with increased urinary-bladder cancer in general; however, a small increased risk in some subgroups, such as heavy users of artificial sweeteners, cannot be unequivocally excluded. With regard to the general population, if sodium saccharin is a risk factor, it is weak, and a causal relationship with cancer cannot be proven or disproven, because of a lack of exposure data and intrinsic limitations of the available epidemiology studies.

##### B.2.1.1.3 Studies on Mechanisms of Carcinogenesis

Extensive studies of the mutagenicity and genotoxicity of saccharin have shown generally negative but occasionally conflicting results. Sodium saccharin is essentially nonmutagenic in conventional bacterial systems but is weakly clastogenic or genotoxic in short-term in vitro and in some in vivo test systems (reviewed by Ashby 1985; IARC 1987a; 1987b; Whysner and Williams 1996). Urine from mice exposed to sodium saccharin was mutagenic in Salmonella typhimurium in one study (Batzinger et al. 1977). Saccharin does not covalently bind to DNA and does not induce unscheduled DNA synthesis in urinarybladder urothelium.

Saccharin-induced carcinogenesis in rats showed a sex predilection for males (Arnold et al. 1980; Taylor et al. 1980; Tisdel et al. 1974), an organ specificity for urinary (Arnold et al. 1980; Fukushima et al. 1983; Schoenig et al. 1985; Taylor et al. 1980; Tisdel et al. 1974), and a dose-response when exposure to dietary concentrations of 1% to 7.5% of the sodium salt of saccharin was begun early in life (beginning at birth or immediately at weaning) and continued for approximately two years (Schoenig et al. 1985). The results of mechanistic studies have shown that certain physiological conditions must be simultaneously or sequentially present for induction of urinarybladder tumorigenesis. These conditions include a urinary pH greater than 6.5, increased urinary sodium concentration, increased urine volume, decreased urine osmolality, and presence of urinary crystals or precipitate, with resulting damage to the urothelium prompting a proliferative (hyperplastic) response of the urinary-bladder epithelium. All of these conditions have been studied extensively in male rats but less so in female rats or in mice. The high levels of urinary protein characteristically produced by male rats may partially explain the sex predilection. The high intrinsic rate of urothelial proliferation at about the time of weaning is also believed to contribute to the observed tumorigenic effects. The urinary milieu in rats, especially male rats, is sufficiently different from that in humans or other species to support the contention that these observations are specific to rats. Pharmacokinetic and metabolism data on sodium saccharin do not explain the male rat’s sensitivity for induction of urinary-bladder neoplasms (Sweatman and Renwick 1979; Sweatman and Renwick 1980).

#### B.2.1.2 Action on Nomination

Saccharin will be removed from the Report on Carcinogens, because the data on cancer in rodents are not sufficient to meet the current criteria to list this chemical as reasonably anticipated to be a human carcinogen. This decision is based on the perception that the observed urinary-bladder tumors in rats arise by mechanisms not relevant to humans, and the lack of data in humans suggesting a carcinogenic hazard.

## References

Allen MJ, Boyland E, Dukes CE, Horning ES, Watson JG. 1957. Cancer of the urinary bladder induced in mice with metabolites of aromatic amines and tryptophan. Br J Cancer. 11:212–228. 10.1038/bjc.1957.29 13460145
Althoff J, Cardesa A, Pour P, Shubik P. 1975. A chronic study of artificial sweeteners in Syrian golden hamsters. Cancer Lett. 1:21–24. 10.1016/S0304-3835(75)94692-3 1235054
Armstrong B, Doll R. 1975. Bladder cancer mortality in diabetics in relation to saccharin consumption and smoking habits. Br J Prev Soc Med. 29:73–81. 10.1136/jech.29.2.73 1182356
Arnold DL, Moodie CA, Grice HC, Charbonneau SM, Stavric B, Collins BT, McGuire PF, Zawidzka ZZ, Munro IC. 1980. Long-term toxicity of ortho-toluenesulfonamide and sodium saccharin in the rat. Toxicol Appl Pharmacol. 52:113–152. 10.1016/0041-008X(80)90253-7 7361306
Ashby J. 1985. The genotoxicity of sodium saccharin and sodium chloride in relation to their cancer-promoting properties. Food Chem Toxicol. 23:507–519. 10.1016/0278-6915(85)90145-0 3891557
Batzinger RP, Ou SY, Bueding E. 1977. Saccharin and other sweeteners: Mutagenic properties. Science. 198:944–946. 10.1126/science.337489 337489
Bryan GT, Erturk E, Yoshida O. 1970. Production of urinary bladder carcinomas in mice by sodium saccharin. Science. 168(3936):1238–1240. 10.1126/science.168.3936.1238 5442712
Cartwright RA, Adib R, Glashan R, Gray BK. 1981. The epidemiology of bladder cancer in West Yorkshire. A preliminary report on non-occupational aetiologies. Carcinogenesis. 2(4):343–347. 10.1093/carcin/2.4.343 7273315
Chowaniec J, Hicks RM. 1979. Response of the rat to saccharin with particular reference to the urinary bladder. Br J Cancer. 39:355–375. 10.1038/bjc.1979.68 36123
Cohen SM, Arai M, Jacobs JB, Friedell GH. 1979. Promoting effect of saccharin and DL-tryptophan in urinary bladder carcinogenesis. Cancer Res. 39:1207–1217. 421204
Cohen SM, Arnold LL, Cano M, Thorgeirsson U, Takayama S. 1996. Lack of effect of sodium saccharin feeding on monkey urine and urinary bladder epithelium [abstract]. Proc Am Assoc Cancer Res. 37:108.
Fitzhugh OG, Nelson AA, Frawley JP. 1951. A comparison of the chronic toxicities of synthetic sweetening agents. J Am Pharm Assoc Am Pharm Assoc. 40:583–586. 10.1002/jps.3030401117 14907466
Frederick CB, Dooley KL, Kodell RL, Sheldon WG, Kadlubar FF. 1989. The effect of lifetime sodium saccharin dosing on mice initiated with the carcinogen 2-acetylaminofluorene. Fundam Appl Toxicol. 12:346–357. 10.1016/0272-0590(89)90051-1 2714533
Fukushima S, Arai M, Nakanowatari J, Hibino T, Okuda M, Ito N. 1983. Differences in susceptibility to sodium saccharin among various strains of rats and other animal species. Gann. 74:8–20. 6840440
Fukushima S, Uwagawa S, Shirai T, Hasegawa R, Ogawa K. 1990. Synergism by sodium L-ascorbate but inhibition by L-ascorbic acid for sodium saccharin promotion of rat two-stage bladder carcinogenesis. Cancer Res. 50:4195–4198. 2364375
Hicks RM, Chowaniec J. 1977. The importance of synergy between weak carcinogens in the induction of bladder cancer in experimental animals and humans. Cancer Res. 37:2943–2949. 872124
Homburger F. 1978. Negative lifetime carcinogen studies in rats and mice fed 50,000 ppm saccharin. In: Galli CL, Paoletti R, Vettorazzi G, editors. Chemical Toxicology of Food. Amsterdam, Netherlands: Elsevier/North-Holland Biomedical Press; p. 359–373.
Hooson J, Hicks RM, Grasso P, Chowaniec J. 1980. ortho-Toluene sulphonamide and saccharin in the promotion of bladder cancer in the rat. Br J Cancer. 42(1):129–147. 10.1038/bjc.1980.211 7426324
Hoover RN, Hartge Strasser P. 1980. Artificial sweeteners and human bladder cancer. Lancet. 315(8173):837–841. 10.1016/S0140-6736(80)91350-1 6103207
Howe GR, Burch JD, Miller AB, Cook GM, Esteve J, Morrison B, Gordon P, Chambers LW, Fodor G, Winsor GM. 1980. Tobacco use, occupation, coffee, various nutrients, and bladder cancer. J Natl Cancer Inst. 64(4):701–713. 6928984
IARC. 1980. Saccharin. In Some Non-Nutritive Sweetening Agents. IARC Monographs on the Evaluation of the Carcinogenic Risk of Chemicals to Humans, vol. 22. Lyon, France: International Agency for Research on Cancer. pp. 111–170.
IARC. 1987 a. Saccharin. In Genetic and Related Effects: An Updating of Selected IARC Monographs from Volumes 1-42. IARC Monographs on the Evaluation of the Carcinogenic Risks to Humans, suppl 6. Lyon, France: International Agency for Research on Cancer. pp. 488–496.
IARC. 1987 b. Saccharin. In Overall Evaluations of Carcinogenicity: An Updating of IARC Monographs Volumes 1-42. IARC Monographs on the Evaluation of the Carcinogenic Risks to Humans, suppl 7. Lyon, France: International Agency for Research on Cancer. pp. 334–339.
JECFA. 1993. Saccharin and its salts. In Toxicological Evaluation of Certain Food Additives and Contaminants. WHO Food Additives Series No. 32. Joint FAO/WHO Expert Committee on Food Additives, International Programme on Chemical Safety.
Kroes R, Peters PW, Berkvens JM, Verschuuren HG, de Vries T, van Esch GJ. 1977. Long term toxicity and reproduction study (including a teratogenicity study) with cyclamate, saccharin and cyclohexylamine. Toxicology. 8:285–300. 10.1016/0300-483X(77)90100-7 595021
Lessel B. 1971. Carcinogenic and teratogenic aspects of saccharin. In Proceedings of the Third International Congress of Food Science and Technology, SOS/70. Chicago, IL: Institute of Food Technologists. pp. 764-770.
McChesney EW, Coulston F, Benitz KF. 1977. Six-year study of saccharin in rhesus monkeys [abstract]. Toxicol Appl Pharmacol. 41:164.
Mommsen S, Aagaard J, Sell A. 1983. A case-control study of female bladder cancer. Eur J Cancer Clin Oncol. 19:725–729. 10.1016/0277-5379(83)90005-6 6683645
Morrison AS, Verhoek WG, Leck I, Aoki K, Ohno Y, Obata K. 1982. Artificial sweeteners and bladder cancer in Manchester, U.K., and Nagoya, Japan. Br J Cancer. 45:332–336. 10.1038/bjc.1982.59 7073930
Nakanishi K, Hirose M, Ogiso T, Hasegawa R, Arai M, Ito N. 1980. Effects of sodium saccharin and caffeine on the urinary bladder of rats treated with n-butyl-n-(4-hydroxybutyl)nitrosamine. Gann. 71:490–500. 7429086
Prasad O, Rai G. 1986. Induction of papillary adenocarcinoma of thyroid in albino mice by saccharin feeding. Indian J Exp Biol. 24:197–199. 3733179
Roe FJC, Levy LS, Carter RL. 1970. Feeding studies on sodium cyclamate, saccharin and sucrose for carcinogenic and tumour-promoting activity. Food Cosmet Toxicol. 8:135–145. 10.1016/S0015-6264(70)80332-7 4316101
Schmähl D. 1973. Lack of carcinogenic effects of cyclamate, cyclohexylamine, and saccharine in rats [in German]. Arzneimittelforschung. 23:1466–1470. 4801331
Schmähl D, Habs M. 1984. Investigations on the carcinogenicity of the artificial sweeteners sodium cyclamate and sodium saccharin in rats in a two-generation experiment [in German]. Arzneimittelforschung. 34:604–606. 6205663
Schoenig GP, Goldenthal EI, Geil RG, Frith CH, Richter WR, Carlborg FW. 1985. Evaluation of the dose response and in utero exposure to saccharin in the rat. Food Chem Toxicol. 23:475–490. 10.1016/0278-6915(85)90142-5 4040096
Sieber SM, Adamson RH. 1978. Long-term studies on the potential carcinogenicity of artificial sweeteners in non-human primates. In: Guggenheim B, editor. Health and Sugar Substitutes. Basel, Switzerland: Karger. pp. 266–271.
Sweatman TW, Renwick AG. 1979. Saccharin metabolism and tumorigenicity. Science. 205:1019–1020. 10.1126/science.472722 472722
Sweatman TW, Renwick AG. 1980. The tissue distribution and pharmacokinetics of saccharin in the rat. Toxicol Appl Pharmacol. 55:18–31. 10.1016/0041-008X(80)90215-X 7191585
Taylor JM, Weinberger MA, Friedman L. 1980. Chronic toxicity and carcinogenicity to the urinary bladder of sodium saccharin in the in utero-exposed rat. Toxicol Appl Pharmacol. 54:57–75. 10.1016/0041-008X(80)90008-3 7394788
Thorgeirsson UP, Dalgard DW, Reeves J, Adamson RH. 1994. Tumor incidence in a chemical carcinogenesis study of nonhuman primates. Regul Toxicol Pharmacol. 19:130–151. 10.1006/rtph.1994.1013 8041912
Tisdel MO, Nees PO, Harris DL, Derse PH. 1974. Long-term feeding of saccharin in rats. In Inglett GE, editor. Symposium: Sweeteners. Westport, CT: Avi Publishing Co. pp. 145-158.
West RW, Sheldon WG, Gaylor DW, Haskin MG, Delongchamp RR, Kadlubar FF. 1986. The effects of saccharin on the development of neoplastic lesions initiated with N-methyl-N-nitrosourea in the rat urothelium. Fundam Appl Toxicol. 7:585–600. 10.1016/0272-0590(86)90108-9 3803753
Whysner J, Williams GM. 1996. Saccharin mechanistic data and risk assessment: Urine composition, enhanced cell proliferation, and tumor promotion. Pharmacol Ther. 71:225–252. 10.1016/0163-7258(96)00069-1 8910956