# Appendix A Cancer Hazards Not Included in the NTP Report on Carcinogens

Certain manufacturing processes, occupations, and other exposure circumstances have been classified as carcinogens by authoritative sources, including the International Agency for Research on Cancer (IARC), the World Cancer Research Fund (WCRF), and the National Toxicology Program (NTP). These cancer hazards are not included in the Report on Carcinogens (RoC) either because of uncertainty as to whether they meet the legislative mandate of the RoC or because certain aspects of these exposures may differ in different parts of the world.

Occupational practices or manufacturing processes classified by IARC or NTP as carcinogenic to humans

- Acheson process, occupational exposure associated with (synthesis of silicon carbide) (IARC 2017)
- Aluminum production, occupational exposures during (IARC 2012b)
- Auramine production (IARC 2012c)
- Coal gasification (IARC 2012d)
- Coal-tar distillation, occupational exposures during (IARC 2012e)
- Coke production (IARC 2012f)
- Hematite mining, underground, with exposure to radon (IARC 2012g)
- Iron and steel founding, occupational exposure during (IARC 2012h)
- Isopropyl alcohol manufacture by the strong-acid process (IARC 2012i)
- Persistent night shift work that causes circadian disruption (NTP 2018)
- Magenta production (IARC 2012a)
- Painter, occupational exposure as a (IARC 2012l)
- Rubber-manufacturing industry, occupational exposures in the (IARC 2012m)
- Ultraviolet radiation from welding (IARC 2018c)

Dietary factors classified as cancer hazards by WCRF (convincing evidence) or IARC (carcinogenic to humans)

- Obesity, overweight, or body fatness (IARC 2018b; WCRF 2018)
- Processed meat (IARC 2018a; WCRF 2018)
- Salted fish, Chinese style (IARC 2012o; WCRF 2018)

Other exposure scenarios classified by IARC or NTP as Cancer Hazards

- Estrogen-only menopausal therapy (IARC 2012n)^1,2^
  1 Estrogens, steroidal are listed in the RoC as known to be human carcinogens based on sufficient evidence of carcinogenicity from studies in humans, which consist mainly of studies of estrogen postmenopausal therapy.
  2 IARC’s conclusions are discussed in the Estrogens, Steroidal substance profile.
- Estrogen-progestogen, menopausal therapy (IARC 2012j)
- Estrogen-progestogen, oral contraceptives (IARC 2012k)^2^

## References

IARC. 2012 a. Magenta and magenta production. In Chemical Agents and Related Occupations. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100F. Lyon, France: International Agency for Research on Cancer. pp. 105–110.
IARC. 2012 b. Occupational exposures during aluminium production. In Chemical Agents and Related Occupations. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100F. Lyon, France: International Agency for Research on Cancer. pp. 215–223.
IARC. 2012 c. Auramine and auramine production. In Chemical Agents and Related Occupations. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100F. Lyon, France: International Agency for Research on Cancer. pp. 101–104.
IARC. 2012 d. Coal gasification. In Chemical Agents and Related Occupations. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100F. Lyon, France: International Agency for Research on Cancer. pp. 145–152.
IARC. 2012 e. Occupational exposures during coal-tar distillation. In Chemical Agents and Related Occupations. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100F. Lyon, France: International Agency for Research on Cancer. pp. 153–160.
IARC. 2012 f. Coke production. In Chemical Agents and Related Occupations. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100F. Lyon, France: International Agency for Research on Cancer. pp. 167–178.
IARC. 2012 g. Internalized ⍺-particle emitting radionuclides. In Radiation. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100D. Lyon, France: International Agency for Research on Cancer. pp. 241–283.
IARC. 2012 h. Occupational exposures during iron and steel founding. In Chemical Agents and Related Occupations. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100F. Lyon, France: International Agency for Research on Cancer. pp. 497–507.
IARC. 2012 i. Isopropyl alcohol manufacture by the strong-acid process. In Chemical Agents and Related Occupations. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100F. Lyon, France: International Agency for Research on Cancer. pp. 479–485.
IARC. 2012 j. Combined estrogen-progestogen menopausal therapy. In Pharmaceuticals. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100A. Lyon, France: International Agency for Research on Cancer. pp. 249–282.
IARC. 2012 k. Combined estrogen-progestogen contraceptives. In Pharmaceuticals. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100A. Lyon, France: International Agency for Research on Cancer. pp. 283–317.
IARC. 2012 l. Occupational exposures as a painter. In Chemical Agents and Related Occupations. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100F. Lyon, France: International Agency for Research on Cancer. pp. 509–539.
IARC. 2012 m. Occupational exposures during rubber manufacturing. In Chemical Agents and Related Occupations. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100F. Lyon, France: International Agency for Research on Cancer. pp. 541–562.
IARC. 2012 n. Estrogen-only menopausal therapy. In Pharmaceuticals. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100A. Lyon, France: International Agency for Research on Cancer. pp. 219–247.
IARC. 2012 o. Chinese-style salted fish. In Personal Habits and Indoor Combustions. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 100E. Lyon, France: International Agency for Research on Cancer. pp. 501–514.
IARC. 2017. Silicon carbide. In Some Nanomaterials and Some Fibres. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 111. Lyon, France: International Agency for Research on Cancer. pp. 243–313.
IARC. 2018a. Red Meat and Processed Meat. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 114. Lyon, France: International Agency for Research on Cancer. 517 pp.
IARC. 2018b. Absence of Excess Body Fatness. IARC Handbooks of Cancer Prevention, vol. 16. Lyon, France: International Agency for Research on Cancer. 658 pp.
IARC. 2018c. Welding, Molybdenum Trioxide, and Indium Tin Oxide. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 118. Lyon, France: International Agency for Research on Cancer. 320 pp.
NTP. 2018. Draft Report on Carcinogens Monograph on Night Shift Work and Light at Night. Research Triangle Park, NC: National Toxicology Program. 350pp. https://ntp.niehs.nih.gov/go/717273
WCRF. 2018. Diet, Nutrition, Physical Activity, and Cancer: A Global Perspective. London, England: World Cancer Research Fund. 116 pp. http://dietandcancerreport.org