# 1-Amino-2-methylanthraquinone

CAS No. 82-28-0

Reasonably anticipated to be a human carcinogen

First listed in the Third Annual Report on Carcinogens (1983)

Figure 1

Chemical Structure of 1-Amino-2-methylanthraquinone

## Carcinogenicity

1-Amino-2-methylanthraquinone is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

### Cancer Studies in Experimental Animals

Oral exposure to 1-amino-2-methylanthraquinone caused tumors in two rodent species and at two different tissue sites. Dietary administration of technical-grade 1-amino-2-methylanthraquinone increased the combined incidence of benign and malignant liver tumors (hepatocellular adenoma and carcinoma) in female mice. In rats, it caused liver cancer in both sexes and increased the combined incidence of benign and malignant kidney tumors (tubular-cell adenoma and carcinoma and adenocarcinoma) in males (NCI 1978).

### Cancer Studies in Humans

No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to 1-amino-2-methylanthraquinone.

## Properties

1-Amino-2-methylanthraquinone is an anthraquinone dye and dye intermediate that exists as an orange solid at room temperature (NCI 1978). It is practically insoluble in water; soluble in acetone, benzene, ethanol, ethylene glycol, monoethyl ether, and linseed oil; and slightly soluble in carbon tetrachloride (ChemIDplus 2009; IARC 1982). Physical and chemical properties of 1-amino-2-methylanthraquinone are listed in Table 1.

Table 1 Properties of 1-Amino-2-methylanthraquinone

Property | Information
Molecular weight | 237.3^a^
Melting point | 206°C^a^
Log K_ow_ | 4.07^b^
Water solubility | 0.332 mg/L at 25°C^b^
Vapor pressure | 3.82 × 10^−8^ mm Hg at 25°C^b^

Sources: ^a^HSDB (2009), ^b^ChemIDplus (2009).

## Use

1-Amino-2-methylanthraquinone was used almost exclusively as a dye and as an intermediate in the production of dyes. It was used as a dye for synthetic fibers, furs, and thermoplastic resins. The only dyes derived from 1-amino-2-methylanthraquinone that were produced in the United States were C.I. acid blue 47, last produced in 1973, and C.I. solvent blue 13, last produced in 1974 (HSDB 2009; IARC 1982).

## Production

U.S. production of 1-amino-2-methylanthraquinone began in 1948 and ended in 1974 (IARC 1982). In 2009, 1-amino-2-methylanthraquinone was produced by one manufacturer in Europe (SRI 2009) and was available from twelve suppliers, including three U.S. suppliers (ChemSources 2009). U.S. imports of 1-amino-2-methylanthraquinone were last reported in 1972, when 120 kg (265 lb) was imported (IARC 1982).

## Exposure

The primary routes of potential human exposure to 1-amino-2-methylanthraquinone are inhalation and dermal contact. The potential for exposure is limited, because 1-amino-2-methylanthraquinone is no longer produced commercially in the United States or reported to be imported. No data were found on environmental releases of 1-amino-2-methylanthraquinone. The potential for occupational exposure was greatest among workers engaged in textile dyeing; however, no data were found on the numbers of workers potentially exposed (HSDB 2009).

## Regulations

### Environmental Protection Agency (EPA)

#### Emergency Planning and Community Right-to-Know Act

Toxics Release Inventory: Listed substance subject to reporting requirements.

## References

ChemIDplus. 2009. ChemIDplus Advanced. National Library of Medicine; Last accessed: 4/21/09. http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources. 2009. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 4/21/09. http://www.chemsources.com/chemonline.html and search on aminomethylanthraquinone.
HSDB. 2009. Hazardous Substances Data Bank. National Library of Medicine; Last accessed: 4/21/09. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1982. Some Aromatic Amines, Anthraquinones and Nitroso Compounds, and Inorganic Fluorides Used in Drinking Water and Dental Preparations. IARC Monographs on the Evaluation of the Carcinogenic Risk of Chemicals to Humans. Vol. 27. Lyon, France: International Agency for Research on Cancer; 1-Amino-2-methylanthraquinone; p. 199–204.
NCI. 1978. Bioassay of 1-Amino-2-Methylanthraquinone for Possible Carcinogenicity. Bethesda, MD: National Institutes of Health. Technical Report Series No. 111. DHEW (NIH) Publication No. 78-1366.
SRI. 2009. Directory of Chemical Producers. Menlo Park, CA: SRI Consulting. Database edition; Last accessed: 4/21/09.