# Acronyms and Abbreviations

A: adenine
AA: aristolochic acid
AAN: aristolochic acid nephropathy
ACGIH: American Conference of Governmental Industrial Hygienists
ADH: alcohol dehydrogenase
AIDS: acquired immunodeficiency syndrome
ALT: alanine transaminase
ANSI: American National Standards Institute
AP1: activator protein 1
AST: American Society of Transplantation
ATLL: adult T-cell leukemia/lymphoma
ATSDR: Agency for Toxic Substances and Disease Registry
BEI: biological exposure index
BEN: Balkan endemic nephropathy
BOP: Bureau of Prisons
BRCA: breast cancer susceptibility proteins
b.w.: body weight
C: cytosine
cART: combined antiretroviral therapy
CAS: Chemical Abstracts Service
CAS No.: Chemical Abstracts Service Registry number
CDC: Centers for Disease Control and Prevention
CFR: Code of Federal Regulations
CHO: Chinese hamster ovary
CI: confidence interval
CIN: cervical intraepithelial neoplasia
C.I.: Colour Index
CoCrMo: cobalt-chromium-molybdenum
COX: cyclooxygenase
CPSC: Consumer Product Safety Commission
CYP: cytochrome P450
2,4-D: 2,4-dichlorophenoxyacetic acid
dA-AAI: 7-(deoxyadenosin-N6-yl)-aristolactam I
dA-AAII: 7-(deoxyadenosin-N6-yl)-aristolactam II
DDD: 1,1-dichloro-2,2-bis(p-chlorophenyl)ethane
DDE: 1,1-dichloro-2,2-bis(p-chlorophenyl)ethylene
DDT: dichlorodiphenyltrichloroethane
dec: decomposes
dG: deoxyguanosine
dG-AAI: 7-(deoxyguanosin-N2-yl)-aristolactam I
dG-AAII: 7-(deoxyguanosin-N2-yl)-aristolactam II
DHHS: Department of Health and Human Services
DHP: dihydropyrrolizine
DHS: Department of Homeland Security
DMDTC: dimethyldithiocarbamate
DNA: deoxyribonucleic acid
DNase: deoxyribonuclease
DNT: dinitrotoluene
DOE: Department of Energy
DoD: Department of Defense
DOT: Department of Transportation
DVA: Department of Veterans Affairs
EBNA: Epstein-Barr nuclear antigen
EBV: Epstein-Barr virus
ed.: edition, editor(s)
ELISA: enzyme-linked immunosorbent assay
E_LUMO_: energy of the lowest unoccupied molecular orbital
EPA: Environmental Protection Agency, United States
F344: Fischer 344 (rats)
FANC: Fanconi anemia complementation group proteins
FDA: Food and Drug Administration, United States
G: guanine
GERD: gastro-esophageal reflux disease
GSH: glutathione
GST: glutathione S-transferase
GST-P+: glutathione S-transferase placental form positive
GSTT1: glutathione S-transferase theta 1
h: hour(s)
HAA5: five common haloacetic acids (bromoacetic acid, chloroacetic acid, dibromoacetic acid, dichloroacetic acid, and trichloroacetic acid)
HAA9: nine common haloacetic acids (bromoacetic acid, bromochloroacetic acid, bromodichloroacetic acid, chloroacetic acid, dibromoacetic acid, dibromochloroacetic acid, dichloroacetic acid, tribromoacetic acid, and trichloroacetic acid)
HAART: highly active antiretroviral therapy
HAM/TSP: HTLV-1-associated myelopathy/tropical spastic paraparesis
HBeAg: hepatitis B e antigen
HBsAg: hepatitis B surface antigen
HBV: hepatitis B virus
HBZ: HTLV-1 basic leucine zipper factor
HCA: heterocyclic amine
HCT/Ps: human cells, tissues, and cellular and tissue-based products
HCV: hepatitis C virus
HHE: Health Hazard Evaluation
HHV: human herpesvirus
HHS: Health and Human Services
HIF-1α: hypoxia-inducible factor 1 alpha
HIV: human immunodeficiency virus
HIVMA: HIV Medicine Association
HpCDD: heptachlorodibenzo-p-dioxin
HPLC: high performance liquid chromatography
HPV: human papillomavirus
HR: hazard ratio
HRSA: Health Resources and Services Administration
HTLV-1: human T-cell lymphotropic virus type 1
HUD: Housing and Urban Development
HxCDD: hexachlorodibenzo-p-dioxin
IARC: International Agency for Research on Cancer
IDLH: immediately dangerous to life and health
IDSA: Infectious Diseases Society of America
IgA: immunoglobulin A
IgG: immunoglobulin G
IL: interleukin
IRIS: Integrated Risk Information System
ISO: International Organization for Standardization
JAK/STAT: Janus kinase/signal transducers and activators of transcription
JM: Johns Manville
K _dis_: dissolution rate
K _ow_: octanol-water partition coefficient
KSHV: Kaposi sarcoma–associated herpesviruses
LET: linear energy transfer
LMP: latent membrane protein
LOD: limit of detection
LT: large T antigen
MALT: mitogen-associated lymphoid tissue
MAP: mitogen-activated protein
MCA 38: murine colon adenocarcinoma cell line
MCL: maximum contaminant level
MCPyV: Merkel cell polyomavirus
MCV: Merkel cell polyomavirus
min: minute(s)
MMVF: man-made (or machine-made) vitreous fibers
mol wt: molecular weight
mRR: meta–relative risk
N/A: not applicable
NAC/AEGL: National Advisory Committee for Acute Exposure Guideline Levels for Hazardous Substances
NADPH: nicotinamide adenine dinucleotide phosphate, reduced form
NAICS: North American Industrial Classification System
NCI: National Cancer Institute
ND: not detected
NextGen: Advancing the Next Generation of Risk Assessment
NF: nuclear factor
NF-κB: nuclear factor kappa-light-chain-enhancer of activated B cells
NHANES: National Health and Nutrition Examination Survey
NHL: non-Hodgkin lymphoma
NIEHS: National Institute of Environmental Health Sciences
NIH: National Institutes of Health
NIOSH: National Institute for Occupational Safety and Health
NK: natural killer
NNK: 4-(N-nitrosomethylamino)-1-(3-pyridyl)-1-butanone
NNN: N-nitrosonornicotine
No.: number
NOHS: National Occupational Hazard Survey
NR: not reported
NRC: Nuclear Regulatory Commission
Nrf2: nuclear respiratory factor 2
NTP: National Toxicology Program
OCDD: octachlorodibenzo-p-dioxin
OPTN: Organ Procurement and Transplantation Network
OR: odds ratio
OSHA: Occupational Safety and Health Administration
PAH: polycyclic aromatic hydrocarbon
PCDD: polychlorinated dibenzodioxin
PCDF: polychlorinated dibenzofuran
PCP: pentachlorophenol
PCR: polymerase chain reaction
PEL: permissible exposure limit
PET: polyethylene terephthalate
PHS: Public Health Service
PI3: phosphoinositide 3
pK_b_: dissociation constant
PVC: polyvinyl chloride
r: correlation coefficient
r^2^: coefficient of determination
R-DHP: R-dihydropyrrolizine
REL: recommended exposure limit
RfC: inhalation reference concentration
RfD: oral reference dose
RNA: ribonucleic acid
RoC: Report on Carcinogens
ROS: reactive oxygen species
RQ: reportable quantity
RR: relative risk (risk ratio or rate ratio)
s: second
S&S: Schleicher & Schuell
S-DHP: S-dihydropyrrolizine
SIR: standardized incidence ratio
SMR: standardized mortality ratio
spp.: species (plural)
ssRNA: single-stranded RNA
sT: small T antigen
STEL: short-term exposure limit
suppl.: supplement
T: thymine
TCBQ: tetrachlorobenzoquinone
TCDD: tetrachlorodibenzo-p-dioxin
TCE: trichloroethylene
TCHQ: tetrachlorohydroquinone
TCLP: toxicity characteristic leaching procedure
TLV: threshold-limit value
TNT: trinitrotoluene
Tox21: Toxicology in the 21st Century
TPQ: threshold planning quantity
TRI: Toxics Release Inventory
TSCA: Toxic Substances Control Act
TSNA: tobacco-specific nitrosamine(s)
TURA: Toxics Use Reduction Act
TWA: time-weighted average
USAI: United States of America Standards Institute
USDA: United States Department of Agriculture
UV: ultraviolet
UVR: ultraviolet radiation
VCA: viral capsid antigen
VOC: volatile organic chemical
vol.: volume
v/v: volume-volume ratio
WC: tungsten carbide
WHO: World Health Organization
wt.: weight
XPA: xeroderma pigmentosum complementation group A
yr: year