# β-Propiolactone

CAS No. 57-57-8

Reasonably anticipated to be a human carcinogen

First listed in the Second Annual Report on Carcinogens (1981)

Figure 1

Chemical Structure of β-Propiolactone

## Carcinogenicity

β-Propiolactone is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

### Cancer Studies in Experimental Animals

β-Propiolactone caused tumors in two rodent species, at several different tissue sites, and by several different routes of exposure. Oral exposure to β-propiolactone caused cancer of the forestomach (squamous-cell carcinoma) in female rats, and dermal exposure caused benign and malignant skin tumors (papilloma that changed to squamous-cell carcinoma) in mice of unspecified sex. Subcutaneous injection of β-propiolactone caused cancer at the injection site in mice of unspecified sex (fibrosarcoma, adenocarcinoma, and squamous-cell carcinoma) and in rats of both sexes (sarcoma) (IARC 1974). In nursing mice, a single intraperitoneal injection of β-propiolactone caused lymphoma in both sexes and liver tumors (hepatocellular tumors) in males.

Since β-propiolactone was listed in the Second Annual Report on Carcinogens, additional studies in experimental animals have been identified. In female mice, oral exposure to β-propiolactone increased the combined incidence of benign and malignant tumors of the forestomach (papilloma and carcinoma) (Hochalter et al. 1988; Wattenberg et al. 1983; Wattenberg et al. 1987). In male rats, intrarectal administration of β-propiolactone caused benign colon tumors (adenomatous polyps) (Hochalter et al. 1988), and inhalation exposure to β-propiolactone caused cancer of the nasal cavity (Sellakumar et al. 1987; Snyder et al. 1986).

### Cancer Studies in Humans

No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to β-propiolactone.

## Properties

β-Propiolactone is a lactone compound with a four-membered ring. It exists as a colorless liquid with a pungent, slightly sweet odor at room temperature (Akron 2009). It is soluble in water, miscible with alcohol, acetone, ether, and chloroform, and probably miscible with most polar organic solvents and lipids (HSDB 2009). It is unstable at room temperature, but stable when stored at 5°C in glass containers (Akron 2009). Physical and chemical properties of β-propiolactone are listed in Table 1.

Table 1 Properties of β-Propiolactone

Property | Information
Molecular weight | 72.1^a^
Specific gravity | 1.146 at 20°C/4°C^a^
Melting point | −33.4°C^a^
Boiling point | 61°C at 20 mm Hg^a^
Log K_ow_ | 0.462^a^
Water solubility | 370 g/L at 25°C^a^
Vapor pressure | 3.4 mm Hg at 25°C^b^
Vapor density relative to air | 2.5^a^

Sources: ^a^HSDB (2009), ^b^ChemIDplus (2009).

## Use

β-Propiolactone was once a commercially important industrial chemical, and more than 85% of the β-propiolactone produced in the United States was used captively to manufacture acrylic acid and esters (HSDB 2009; IARC 1974). However, β-propiolactone has been replaced in newer manufacturing methods (Bauer 2003). β-Propiolactone has been used to sterilize blood plasma, vaccines, tissue grafts, surgical instruments, and enzymes; as a vapor-phase disinfectant in enclosed spaces; and in organic synthesis (IARC 1974). It has been used as a sporicide against vegetative bacteria, pathogenic fungi, and viruses (HSDB 2009). β-Propiolactone has also been used to inactivate viruses for use in vaccines for animals and humans (Kurogi et al. 1978; Levy et al. 1975; Parker 1975; Scheidler et al. 1998).

## Production

β-Propiolactone was first produced commercially in the United States in 1958, and one U.S. company produced β-propiolactone from 1958 until at least 1973 (IARC 1974). U.S. production was approximately 22 million kilograms (48.5 million pounds) in 1972, but less than 454 kg (1,000 lb) in 1975 (HSDB 2009). No data on current production of β-propiolactone were found. In 2009, β-propiolactone was produced by one manufacturer, in Europe (SRI 2009), and was available from twelve suppliers, including seven U.S. suppliers (ChemSources 2009). No data on U.S. imports or exports of β-propiolactone were found.

## Exposure

Because β-propiolactone is no longer used as a sterilant in medical procedures or in food, the potential for exposure of the general population is limited (HSDB 2009). Potential exposure to waste effluents from production and manufacturing plants is minimal, because of β-propiolactone’s short half-life in water (IARC 1974). Occupational exposure may occur by inhalation and dermal contact at industrial facilities where β-propiolactone is used as a chemical intermediate. Occupational exposure may also occur in laboratories where it is used to inactivate viruses for research and vaccine applications. The National Occupational Hazard Survey (conducted from 1972 to 1974) estimated that 575 workers potentially were exposed to β-propiolactone (NIOSH 1976). No more recent exposure estimates were found.

## Regulations

### Environmental Protection Agency (EPA)

#### Clean Air Act

National Exposure Standards for Hazardous Air Pollutants: Listed as a hazardous air pollutant.

#### Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 10 lb.

#### Emergency Planning and Community Right-to-Know Act

Toxics Release Inventory: Listed substance subject to reporting requirements.

Reportable quantity (RQ) = 10 lb.

Threshold planning quantity (TPQ) = 500 lb.

### Mine Safety and Health Administration (MSHA, Dept. of Labor)

To control airborne exposure, β-propiolactone shall not be used or stored except by competent persons under laboratory conditions approved by a nationally recognized agency acceptable to the Secretary.

### Occupational Safety and Health Administration (OSHA, Dept. of Labor)

Potential occupational carcinogen: Engineering controls, work practices, and personal protective equipment are required.

## Guidelines

### American Conference of Governmental Industrial Hygienists (ACGIH)

Threshold limit value – time-weighted average (TLV-TWA) = 0.5 ppm.

### National Institute for Occupational Safety and Health (NIOSH, CDC, HHS)

β-propiolactone is listed as a potential occupational carcinogen.

## References

Akron. 2009. The Chemical Database. The Department of Chemistry at the University of Akron; Last accessed: 6/4/09. http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
Bauer WJ. 2003. Acrylic acid and derivatives. In Kirk-Othmer Encyclopedia of Chemical Technology, vol. 1. Online ed. New York, NY: John Wiley & Sons. pp. 342–369. 10.1002/0471238961.0103182502012105.a01.pub2 10.1002/0471238961.0103182502012105.a01.pub2
ChemIDplus. 2009. ChemIDplus Advanced. National Library of Medicine; Last accessed: 6/4/09. http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources. 2009. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 6/4/09. http://www.chemsources.com/chemonline.html and search on propiolactone.
Hochalter JB, Wattenberg LW, Coccia JB, Galbraith AR. 1988. Inhibition of β-propiolactone-induced neoplasia of the forestomach and large bowel by 4-mercaptobenzene sulfonate in mice and rats. Cancer Res. 48(10):2740–2743. 3359434
HSDB. 2009. Hazardous Substances Data Bank. National Library of Medicine; Last accessed: 6/4/09. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1974. β-Propiolactone. In Some Aromatic Amines, Hydrazine and Related Substances, N-Nitroso Compounds and Miscellaneous Alkylating Agents. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans, vol. 4. Lyon, France: International Agency for Research on Cancer. pp. 259–269.
Kurogi H, Inaba Y, Takahashi E, Sato K, Goto Y, Satoda K, Omori T, Hatakeyama H. 1978. Development of inactivated vaccine for Akabane disease. Natl Inst Anim Health Q (Tokyo). 18(3-4):97–108. 740047
Levy R, Spira G, Zakay-Rones Z. 1975. Newcastle disease virus pathogenesis in the respiratory tract of local or systemic immunized chickens. Avian Dis. 19(4):700–706. 10.2307/1589183 1200946
NIOSH. 1976. National Occupational Hazard Survey (1972-74). Cincinnati, OH: U.S. Department of Health and Human Services, U.S. Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health. DHEW (NIOSH) Publication No. 78-114.
Parker J. 1975. Inactivation of African horse-sickness virus by betapropiolactone and by pH. Arch Virol. 47(4):357–365. 10.1007/BF01347977 237497
Scheidler A, Rokos K, Reuter T, Ebermann R, Pauli G. 1998. Inactivation of viruses by beta-propiolactone in human cryo poor plasma and IgG concentrates. Biologicals. 26(2):135–144. 10.1006/biol.1998.0125 9811521
Sellakumar AR, Snyder CA, Albert RE. 1987. Inhalation carcinogenesis of various alkylating agents. J Natl Cancer Inst. 79(2):285–289. 3474462
Snyder CA, Garte SJ, Sellakumar AR, Albert RE. 1986. Relationships between the levels of binding to DNA and the carcinogenic potencies in rat nasal mucosa for three alkylating agents. Cancer Lett. 33(2):175–181. 10.1016/0304-3835(86)90022-4 3791188
SRI. 2009. Directory of Chemical Producers. Menlo Park, CA: SRI Consulting. Database edition; Last accessed: 6/4/09.
Wattenberg LW, Borchert P, Destafney CM, Coccia JB. 1983. Effects of p-methoxyphenol and diet on carcinogen-induced neoplasia of the mouse forestomach. Cancer Res. 43(10):4747–4751. 6309375
Wattenberg LW, Hochalter JB, Galbraith AR. 1987. Inhibition of β-propiolactone-induced mutagenesis and neoplasia by sodium thiosulfate. Cancer Res. 47(16):4351–4354. 3607767