# Nitrosourea Chemotherapeutic Agents

## Introduction

Figure 1

Generic Nitrosourea Structure

Five nitrosourea chemotherapeutic agents are listed in the Report on Carcinogens as individual chemicals and not as a class. The generic structure for a nitrosourea is shown above (the simplest member of the nitrosourea class, N-nitrosourea, has hydrogen atoms for the R_1_, R_2_, and R_3_ groups). The five nitrosourea chemotherapeutic agents share a common mechanism of action for their cytotoxicity and antitumor activity, which result from their nonenzymatic decomposition to produce products with alkylating and carbamoylating activities (Chabner et al. 2001; Lemoine et al. 1991). The 2-chloroethylnitrosoureas (CENUs)—1-(2-chloroethyl)-3-cyclohexyl)-1-nitrosourea (CCNU, lomustine), bis(chloroethyl) nitrosourea (BCNU, carmustine), 1-(2-chloroethyl)-3-(4-methylcyclohexyl)-1-nitrosourea (methyl-CCNU, semustine), and chlorozotocin—degrade to form the 2-chloroethyl carbonium ion, which is a strong electrophile capable of alkylating guanine, cytidine, and adenine. If the chloride atom is displaced, intra- or inter-strand cross-links of DNA can result. Interstrand cross-links are considered to be associated with the cytotoxicity of nitrosoureas. Streptozotocin differs from the other four nitrosurea compounds in that it does not contain the 2-chloroethylnitrosourea group. Spontaneous degradation of nitrosourea compounds also can produce organic isocyanates that can carbamoylate lysine residues of proteins, and this reaction may inactivate some DNA repair enzymes. Of these five nitrosoureas, chlorozotocin and streptozotocin have low carbamoylating activity.

One of the nitrosourea compounds, methyl-CCNU, is listed as known to be a human carcinogen, and CCNU, BCNU, chlorozotocin, and streptozotocin are listed as reasonably anticipated to be a human carcinogen. In addition, two nitrosamines that share the nitrosourea structure, N-nitroso-N-methylurea and N-nitroso-N-ethylurea (see their profiles under Nitrosamines) are also listed as reasonably anticipated to be a human carcinogen.

## Bis(chloroethyl) Nitrosourea

CAS No. 154-93-8

Reasonably anticipated to be a human carcinogen

First listed in the Fourth Annual Report on Carcinogens (1985)

Also known as BCNU, carmustine, or N,N′-bis(2-chloroethyl) nitrosourea

Figure 2

Chemical Structure of Bis(chloroethyl) Nitrosourea

### Carcinogenicity

Bis(chloroethyl) nitrosourea (BCNU) is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

#### Cancer Studies in Experimental Animals

Exposure to BCNU by injection caused tumors in rats and mice at several different tissue sites. Lung tumors resulted from intraperitoneal injection of BCNU in rats of both sexes or intravenous injection in male rats, and tumors in the peritoneal cavity also were observed in male rats following intraperitoneal injection. Dermal exposure of mice to BCNU caused an early appearance of skin tumors induced by exposure to ultraviolet B radiation (IARC 1981a; 1982a).

Since BCNU was listed in the Fourth Annual Report on Carcinogens, an additional study in rats has been identified, in which BCNU administered by intravenous injection caused lung cancer (adenocarcinoma) and increased the incidence of neurogenic tumors (oligodendroglioma) (Eisenbrand 1984; Habs and Schmähl 1984).

#### Cancer Studies in Humans

The data available from studies in humans were inadequate to evaluate the relationship between human cancer and exposure specifically to BCNU. No epidemiological studies have evaluated exposure only to BCNU. However, BCNU is associated with the development of acute nonlymphocytic leukemia following its use with other anticancer therapies in the treatment of preexisting cancer (IARC 1987).

### Properties

BCNU is bifunctional alkylating agent that is used as an antineoplastic agent. It is a chloroethyl nitrosourea compound that is an orange-yellow to light-yellow powder at room temperature (Akron 2009; Chabner et al. 2001; IARC 1981a). BCNU is only slightly soluble in water and 50% ethanol, but is soluble in ethanol and lipids. It is sensitive to oxidation and hydrolysis at neutral pH with a half life of 98 minutes (IARC 1981a). Physical and chemical properties of BCNU are listed in Table 1.

Table 1 Properties of Bis(chloroethyl) Nitrosourea

Property | Information
Molecular weight | 214.0^a^
Melting point | 31°C^b^
Log K_ow_ | 1.53^b^
Water solubility | 4 g/L at 25°C^b^
Vapor pressure | 3.69 × 10^−5^ mm at Hg 25°C^b^
Dissociation constant (pK_a_) | 10.19^a^

Sources: ^a^Akron (2009), ^b^ChemIDplus (2009).

### Use

BCNU has been used since 1971 as an anticancer drug and in 1977 was approved by the U.S. Food and Drug Administration, as carmustine, to be marketed for the treatment of Hodgkin disease, non-Hodgkin lymphoma, multiple myeloma, and primary or metastatic brain tumors (FDA 2009c; IARC 1981a; MedlinePlus 2009b). It has also been used to treat malignant melanoma, breast cancer, gastrointestinal cancer, Ewing sarcoma, and Burkitt lymphoma and to be applied to the skin to treat mycosis fungoides (MedlinePlus 2009b). BCNU may be used alone or in combination with other antineoplastic agents (ClinicalTrials 2009b).

### Production

No data on production volumes of BCNU were found. In 2009, BCNU was available from nine suppliers worldwide, including seven U.S. suppliers (ChemSources 2009b). Carmustine is the active ingredient in two pharmaceutical products, an intracranial implant and an injectable drug, which are available from two different pharmaceutical companies (FDA 2009h). The injectable product is available in 100-mg vials, and the implantable product comes in a 7.7-mg size.

### Exposure

The primary routes of human exposure to BCNU are injection (FDA 2009h), and dermal contact in patients (MedlinePlus 2009b). Reported doses of the injectable drug are 100 to 250 mg/m^2^ of body surface area daily by intravenous injection for two or three days (IARC 1981a). In 2009, 159 clinical trials involving BCNU alone or in combination with other antineoplastic agents and treatments were in progress or recently completed (ClinicalTrials 2009b). Health professionals and support staff (including custodians) may be exposed to BCNU by dermal contact, inhalation, and accidental ingestion during drug preparation, administration, or cleanup of medical waste, including excretions from treated patents (NIOSH 2004; Zimmerman et al. 1981). The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that 14,122 health-services workers, including 10,338 women, potentially were exposed to BCNU (NIOSH 1990c).

### Regulations

#### Food and Drug Administration (FDA)

Carmustine is a prescription drug subject to labeling and other requirements.

### Guidelines

#### National Institute for Occupational Safety and Health (NIOSH)

A comprehensive set of guidelines has been established to prevent occupational exposures to hazardous drugs in health-care settings.

#### Occupational Safety and Health Administration (OSHA)

A comprehensive set of guidelines has been established to prevent occupational exposures to hazardous drugs in health-care settings.

## 1-(2-Chloroethyl)-3-cyclohexyl-1-nitrosourea

CAS No. 13010-47-4

Reasonably anticipated to be a human carcinogen

First listed in the Fourth Annual Report on Carcinogens (1985)

Also known as CCNU or lomustine

Figure 3

Chemical Structure of 1-(2-Chloroethyl)-3-cyclohexyl-1-nitrosourea

### Carcinogenicity

1-(2-Chloroethyl)-3-cyclohexyl-1-nitrosourea (CCNU) is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

#### Cancer Studies in Experimental Animals

Exposure to CCNU by injection caused tumors in rodents. Lung tumors resulted from intraperitoneal injection of CCNU in rats of both sexes or intravenous injection in male rats (IARC 1981b; 1982b). Following intraperitoneal injection of CCNU, a slight increase in the incidence of malignant lymphoma (lymphosarcoma) was observed in mice of both sexes.

#### Cancer Studies in Humans

The data available from studies in humans were inadequate to evaluate the relationship between human cancer and exposure specifically to CCNU. In several reported cases, cancer patients who received CCNU developed leukemia; however, all but one of these patients had also been treated with other cytotoxic agents and/or irradiation (IARC 1981b; 1982b).

### Properties

CCNU is a bifunctional alkylating agent that is used as an antineoplastic agent. It is a chloroethyl nitrosourea compound that is a yellow powder at room temperature. It is practically insoluble in water, soluble in ethanol, 0.1 N hydrochloric acid, and sodium hydroxide, and highly soluble in lipids. It may be oxidized or hydrolyzed at room temperature and neutral pH with a half-life of 117 minutes (HSDB 2009; IARC 1981b; 1987). Physical and chemical properties of CCNU are listed in Table 2.

Table 2 Properties of 1-(2-Chloroethyl)-3-cyclohexyl-1-nitrosourea

Property | Information
Molecular weight | 233.7^a^
Melting point | 88°C to 90°C^b^
Log K_ow_ | 2.83^b^
Water solubility | 111 mg/L at 25°C^b^
Vapor pressure | 1.01 × 10^−5^ mm Hg at 25°C^b^

Sources: ^a^HSDB (2009); ^b^ChemIDplus (2009)

### Use

CCNU is an oral anticancer drug that was approved by the U.S. Food and Drug Administration in 1976 for marketing, as lomustine (FDA 2009e). CCNU is used alone or in combination with other antineoplastic agents, including procarbazine and vincristine, etoposide and prednimustine, and other combinations (HSDB 2009; IARC 1981b). It is used primarily in the treatment of Hodgkin disease and brain tumors, but it has also been used to treat other cancer, including lung cancer, non-Hodgkin lymphoma, malignant melanoma, breast cancer, kidney cancer, and cancer of the gastrointestinal tract (MedlinePlus 2009c). It has also been applied to the skin to treat mycosis fungoides and psoriasis.

### Production

CCNU was first synthesized in 1966 (IARC 1981b). In 2009, it was produced by two manufacturers, one in China and one in Europe (SRI 2009), and was available from eighteen suppliers, including nine U.S. suppliers (ChemSources 2009c). CNNU (lomustine) is the active ingredient in three products (capsules in strengths of 10, 40, and 100 mg) from a single pharmaceutical company (FDA 2009b).

### Exposure

The primary route of human exposure to CCNU is ingestion during its use as a pharmaceutical product; however, exposure potentially can also occur through inhalation and dermal contact (Akron 2009; MedlinePlus 2009c). The recommended dose for adults and children is 130 mg/m^2^ of body surface, given as a single oral dose every six weeks (IARC 1981b). In 2009, 45 clinical trials involving CCNU were in progress or recently completed, including 12 that had not completed patient recruitment (ClinicalTrials 2009c). Health professionals and support staff (including custodians) may be exposed by dermal contact, inhalation, or accidental ingestion during drug preparation, administration, or cleanup of medical waste, including excretions from treated patents (NIOSH 2004; Zimmerman et al. 1981). The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that 2,457 health-services workers, including 1,069 women, potentially were exposed to CCNU (NIOSH 1990d).

### Regulations

#### Consumer Product Safety Commission (CPSC)

Any orally administered prescription drug for human use requires child-resistant packaging.

#### Food and Drug Administration (FDA)

Lomustine is a prescription drug subject to labeling and other requirements.

### Guidelines

#### National Institute for Occupational Safety and Health (NIOSH)

A comprehensive set of guidelines has been established to prevent occupational exposures to hazardous drugs in health-care settings.

#### Occupational Safety and Health Administration (OSHA)

A comprehensive set of guidelines has been established to prevent occupational exposures to hazardous drugs in health-care settings.

## 1-(2-Chloroethyl)-3-(4-methylcyclohexyl)-1-nitrosourea

CAS No. 13909-09-6

Known to be a human carcinogen

First listed in the Sixth Annual Report on Carcinogens (1991)

Also known as methyl-CCNU, MeCCNU, or semustine

Figure 4

Chemical Structure of 1-(2-Chloroethyl)-3-(4-methylcyclohexyl)-1-nitrosourea

### Carcinogenicity

1-(2-Chloroethyl)-3-(4-methylcyclohexyl)-1-nitrosourea (methyl-CCNU) is known to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in humans.

#### Cancer Studies in Humans

An increased relative risk (over 12-fold) for nonlymphocytic leukemia was found among patients with gastrointestinal cancer who were treated with methyl-CCNU in several clinical trials; 14 cases of leukemic disorders were reported among 2,067 patients given methyl-CCNU, compared with only 1 case of acute nonlymphocytic leukemia among 1,566 patients given other therapies (Boice et al. 1983). A later analysis of this study found that the risk of leukemia increased with increasing cumulative dose of methyl-CCNU, reaching a relative risk of about 40-fold, adjusted for survival time, among patients treated with the highest dose (Boice et al. 1986; IARC 1987).

#### Cancer Studies in Experimental Animals

There is limited evidence for the carcinogenicity of methyl-CCNU in experimental animals (Weisburger 1977). Methyl-CCNU administered by intravenous injection caused lung tumors in male rats. Administered by intraperitoneal injection, it increased the total incidence of all tumors in male rats and slightly increased the incidence of leukemia and malignant lymphoma (lymphosarcoma) in female mice (IARC 1987).

### Properties

Methyl-CCNU is a direct-acting bifunctional alkylating agent that has been tested for use as an antineoplastic agent. It is a chloroethyl nitrosourea compound that is a light-yellow powder at room temperature (Akron 2009; IARC 1987). It is practically insoluble in water (ChemIDplus 2009). Physical and chemical properties of methyl-CCNU are listed in Table 3.

Table 3 Properties of 1-(2-Chloroethyl)-3-(4-methylcyclohexyl)-1-nitrosourea

Property | Information
Molecular weight | 247.7^a^
Melting point | 70°C^b^
Log K_ow_ | 3.3^a^
Water solubility | 0.037 g/L at 25°C^a^
Vapor pressure | 5.61 × 10^−6^ mm Hg at 25°C^a^

Sources: ^a^ChemIDplus (2009), ^b^Akron (2009).

### Use

Methyl-CCNU is an investigational chemotherapy drug that has been used in clinical trials to treat several types of cancer, including brain cancer, malignant melanoma, lung cancer, and gastrointestinal-tract cancer (Boice et al. 1983). As of 2009, it had not been approved by the U.S. Food and Drug Administration for any uses (FDA 2009a).

### Production

No data on U.S. production, imports, or exports of methyl-CCNU were found. In 2009, methyl-CCNU was available from eight suppliers worldwide, including six U.S. suppliers (ChemSources 2009d).

### Exposure

The most direct exposure to methyl-CCNU is of cancer patients participating in clinical trials of treatment regimens that include methyl-CCNU. In 2009, two completed clinical trials involving methyl-CCNU were identified (ClinicalTrials 2009d). The typical oral dose is 125 to 200 mg/m^2^ of body surface area, repeated every six weeks (Parfitt 1999). Health professionals and support staff (including custodians) may be exposed to methyl-CCNU by dermal contact, inhalation, or accidental ingestion during drug preparation, administration, or cleanup of medical waste, including excretions from treated patents (NIOSH 2004; Zimmerman et al. 1981). The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that 229 workers, including 82 women, potentially were exposed to methyl-CCNU (NIOSH 1990e).

### Regulations

No specific regulations or guidelines relevant to reduction of exposure to methyl-CCNU were identified.

## Chlorozotocin

CAS No. 54749-90-5

Reasonably anticipated to be a human carcinogen

First listed in the Eighth Report on Carcinogens (1998)

Figure 5

Chemical Structure of Chlorozotocin

### Carcinogenicity

Chlorozotocin is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals and because it is a member of a well-defined, structurally related class of substances listed in the Report on Carcinogens as either known to be a human carcinogen or reasonably anticipated to be a human carcinogen.

#### Cancer Studies in Experimental Animals

Exposure to chlorozotocin caused tumors at several different tissue sites in rats. Chlorozotocin administered to male rats by intravenous injection caused cancer of the nervous system, lungs, and forestomach. Intraperitoneal injection of chlorozotocin caused tumors in the abdominal cavity (sarcoma or mesothelioma) in rats of both sexes (IARC 1990).

#### Cancer Studies in Humans

No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to chlorozotocin.

#### Studies on Mechanisms of Carcinogenesis

Chlorozotocin is structurally related to other chloroethyl nitrosoureas, one of which, 1-(2-chloroethyl)-3-(4-methylcyclohexyl)-1-nitrosourea, is listed in the Report on Carcinogens as known to be a human carcinogen, and two of which, bis(chloroethyl) nitrosourea and 1-(2-chloroethyl)-3-cyclohexyl-1-nitrosourea, are listed in the Report on Carcinogens as reasonably anticipated to be a human carcinogen. Chlorozotocin exerts its adverse effects through the formation of mono- and bi-functional alkylating agents. It causes genetic damage in a wide variety of bacterial and mammalian cellular assays, inducing mutations in bacteria, yeast, insects, and cultured mammalian cells and DNA damage in human, mouse, and Chinese hamster cells in vitro and in bone-marrow cells in rats exposed in vivo (IARC 1990). In rats subcutaneously implanted with rhabdomyosarcoma cells, chlorozotocin administered by intraperitoneal injection increased metastasis to the lungs (Pauwels et al. 1985). There is no evidence to suggest that the mechanisms by which chlorozotocin causes tumors in experimental animals would not also operate in humans.

### Properties

Chlorozotocin is a nitrosourea compound that exists as ivory-colored crystals at room temperature. It is soluble in water and is stable in solution at room temperature for up to 3 hours and under refrigeration for 24 hours. The powder form of chlorozotocin is stable under refrigeration for two years. The spontaneous, nonenzymatic degradation of chlorozotocin results in formation of DNA-alkylating and protein-carbamoylating moieties (Chabner et al. 2001). Physical and chemical properties of chlorozotocin are listed in Table 4.

Table 4 Properties of Chlorozotocin

Property | Information
Molecular weight | 265.7^a^
Melting point | 147°C to 148°C (decomposes with evolution of gas)^b^
Log K_ow_ | −1.02^b^
Water solubility | 1.8 g/L at 25°C^a^
Vapor pressure | 3.98 × 10^−14^ mm Hg at 25°C^a^
Dissociation constant (pK_a_) | 9.08^c^

Sources: ^a^ChemIDplus (2009), ^b^HSDB (2009), ^c^Akron (2009).

### Use

Chlorozotocin is a cytostatic agent that has been used to treat melanoma and multiple myeloma and cancer of the stomach, large intestine, pancreas, and lung (IARC 1990). As of 2009, no products containing chlorozotocin as an active ingredient had been approved for use by the U.S. Food and Drug Administration (FDA 2009d).

### Production

Synthesis of chlorozotocin occurs by nitrosation of the urea derivative prepared from d-glucosamine and 2-chloroethyl isocyanate. Chlorozotocin was reported to be produced in the United States (IARC 1990), but no production data were found, nor any data on U.S. imports or exports of chlorozotocin, and no U.S. suppliers were identified.

### Exposure

The primary route of potential human exposure to chlorozotocin is intravenous administration. Chlorozotocin has been given intravenously at doses of 100 to 225 mg/m^2^ of body surface area (IARC 1990). Health professionals and support staff (including custodians) may be exposed to chlorozotocin by dermal contact, inhalation, or accidental ingestion during drug preparation, administration, or cleanup of medical waste, including excretions from treated patients (NIOSH 2004; Zimmerman et al. 1981). The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that 267 health-services workers, including 223 women, potentially were exposed to chlorozotocin (NIOSH 1990a).

### Regulations

No specific regulations or guidelines relevant to reduction of exposure to chlorozotocin were identified.

### Guidelines

#### National Institute for Occupational Safety and Health (NIOSH)

A comprehensive set of guidelines has been established to prevent occupational exposures to hazardous drugs in health-care settings.

#### Occupational Safety and Health Administration (OSHA)

A comprehensive set of guidelines has been established to prevent occupational exposures to hazardous drugs in health-care settings.

## Streptozotocin

CAS No. 18883-66-4

Reasonably anticipated to be a human carcinogen

First listed in the Second Annual Report on Carcinogens (1981)

Figure 6

Chemical Structure of Streptozotocin

### Carcinogenicity

Streptozotocin is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

#### Cancer Studies in Experimental Animals

Exposure to streptozotocin by injection caused tumors at several different tissue sites in three rodent species. Administration of streptozotocin by intraperitoneal injection caused kidney tumors in rats and mice of both sexes. In mice, it also caused lung tumors in both sexes and uterine tumors in females. In rats, it also caused pancreatic tumors in both sexes, liver tumors in females, and cancer of the abdominal cavity (sarcoma of the peritoneum) in males. In hamsters, it caused tumors of the liver (hepatocellular carcinoma) or bile duct (cholangioma) in both sexes (IARC 1978). A single intravenous injection of streptozotocin caused malignant or benign kidney tumors (adenocarcinoma, sarcoma, or adenoma) in rats of both sexes (IARC 1974; 1978; Rakieten and Gordon 1975).

Since streptozotocin was listed in the Second Annual Report on Carcinogens, additional studies in rodents have been identified. Intravenous injection of streptozotocin increased the incidence of benign or malignant kidney tumors in mice of both sexes (Delahunt et al. 1995; Hard 1985) and the incidence of benign tumors of the kidney, pancreas, liver, bile duct, and testis in male rats (Feldman et al. 1977; Kazumi et al. 1978; Okawa and Doi 1983). Pancreatic tumors (islet-cell adenoma, ductular adenoma, or insulinoma) also were observed in hamsters of both sexes after a single intravenous injection of streptozotocin (Pour and Patil 1983) and in male hamsters after intraperitoneal injection (Pour et al. 1990).

#### Cancer Studies in Humans

The data available from epidemiological studies are inadequate to evaluate the relationship between human cancer and exposure specifically to streptozotocin.

### Properties

Streptozotocin is a nitrosourea compound that exists as pale-yellow or ivory pointed platelets or prisms at room temperature (HSDB 2009). It is soluble in water, lower alcohols, and ketones, slightly soluble in most other polar organic solvents, and insoluble in nonpolar organic solvents. Streptozotocin is sensitive to humidity and light and decomposes rapidly at temperatures over 70°C (IARC 1974). It is most stable in acidic solutions and decomposes rapidly in alkaline solutions. Physical and chemical properties of streptozotocin are listed in Table 5.

Table 5 Properties of Streptozotocin

Property | Information
Molecular weight | 265.2^a^
Melting point | 115°C^b^
Log K_ow_ | −1.45^b^
Water solubility | 5.070 g/L at 25°C^b^
Vapor pressure | 1.74 × 10^−12^ mm Hg at 25°C^b^
Dissociation constant (pK_a_) | 1.35^a^

Sources: ^a^HSDB (2009); ^b^ChemIDplus (2009)

### Use

Streptozotocin was approved by the U.S. Food and Drug Administration in 1982, as Zanosar, to be marketed for treatment of pancreatic cancer (FDA 2009f). It has also been used to induce and study diabetes, because it has a specific toxic action on pancreatic β-cells (IARC 1974; 1978). Streptozotocin has been investigated as a potential antibacterial agent, but has never been used commercially for this purpose. It is used to treat pancreatic islet-cell cancer, pancreatic adenocarcinoma, Hodgkin disease, colorectal cancer, liver cancer (hepatocellular carcinoma), adrenal-gland cancer (pheochromocytoma), lung cancer (epidermoid carcinoma), lymphocytic lymphoma, Burkitt lymphoma, acute lymphocytic leukemia, malignant melanoma, metastatic sarcoma, and malignant carcinoid tumors (IARC 1978; MedlinePlus 2009a).

### Production

Streptozotocin is derived from the bacterium Streptomyces achromogenes and has been synthesized by three different procedures (HSDB 2009; IARC 1978). In 2009, it was produced by one manufacturer worldwide, in the United States (SRI 2009), and was available from 24 suppliers, including 15 U.S. suppliers (ChemSources 2009a). No data on U.S. imports or exports of streptozotocin were found.

### Exposure

Streptozotocin is available as an injectable product in 1-g vials from a single U.S. pharmaceutical company (FDA 2009g). In 2009, eight clinical trials using streptozotocin in combination with other antineoplastic agents as treatment for pancreatic, brain, colorectal, adrenal cortical, or various other endocrine tumors were in progress or recently completed (ClinicalTrials 2009a). Health professionals and support staff (including custodians) may be exposed to streptozotocin by dermal contact, inhalation, or accidental ingestion during drug preparation, administration, or cleanup of medical waste, including excretions from treated patients (NIOSH 2004; Zimmerman et al. 1981). The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that 2,074 workers, including 1,713 women, potentially were exposed to streptozotocin (NIOSH 1990b).

### Regulations

#### Environmental Protection Agency (EPA)

Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 1 lb.

##### Resource Conservation and Recovery Act

Listed Hazardous Waste: Waste code for which the listing is based wholly or partly on the presence of streptozotocin = U206.

Listed as a hazardous constituent of waste.

#### Food and Drug Administration (FDA)

Streptozotocin is a prescription drug subject to labeling and other requirements.

### Guidelines

#### National Institute for Occupational Safety and Health (NIOSH)

A comprehensive set of guidelines has been established to prevent occupational exposures to hazardous drugs in health-care settings.

#### Occupational Safety and Health Administration (OSHA)

A comprehensive set of guidelines has been established to prevent occupational exposures to hazardous drugs in health-care settings.

## References

Akron. 2009. The Chemical Database. The Department of Chemistry at the University of Akron; Last accessed: 8/12/09. http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
Boice JD, Greene MH, Killen JY Jr, Ellenberg SS, Fraumeni JF Jr, Keehn RJ, McFadden E, Chen TT, Stablein D. 1986. Leukemia after adjuvant chemotherapy with semustine (methyl-CCNU)—Evidence of a dose-response effect. N Engl J Med. 314(2):119–120. 10.1056/NEJM198601093140214 3941685
Boice JD Jr, Greene MH, Killen JY Jr, Ellenberg SS, Keehn RJ, McFadden E, Chen TT, Fraumeni JF Jr. 1983. Leukemia and preleukemia after adjuvant treatment of gastrointestinal cancer with semustine (methyl-CCNU). N Engl J Med. 309(18):1079–1084. 10.1056/NEJM198311033091802 6353233
Chabner BA, Ryan DP, Paz-Ares L, Garcia-Carbonero R, Calabresi P. 2001. Antineoplastic agents. In Hardman JG, Limbird LE, Gilman A, editors. Goodman and Gilman’s The Pharmacological Basis of Therapeutics, 10th ed. New York, NY: McGraw-Hill. pp. 1389–1459.
ChemIDplus. 2009. ChemIDplus Advanced. National Library of Medicine; Last accessed: 8/12/09. http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources. 2009a. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 8/12/09. http://www.chemsources.com/chemonline.html and search on streptozotocin.
ChemSources. 2009b. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 8/12/09. http://www.chemsources.com/chemonline.html and search on carmustine.
ChemSources. 2009c. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 8/12/09. http://www.chemsources.com/chemonline.html and search on lomustine.
ChemSources. 2009d. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 8/12/09. http://www.chemsources.com/chemonline.html and search on semustine.
ClinicalTrials. 2009a. Streptozotocin. National Institutes of Health; Last accessed: 8/12/09. http://clinicaltrials.gov/ct2/results?term=streptozotocin
ClinicalTrials. 2009b. Carmustine. National Institutes of Health; Last accessed: 8/12/09. http://clinicaltrials.gov/ct2/results?term=carmustine
ClinicalTrials. 2009c. Lomustine. National Institutes of Health; Last accessed: 8/12/09. http://clinicaltrials.gov/ct2/results?term=lomustine
ClinicalTrials. 2009d. Semustine. National Institutes of Health; Last accessed: 8/12/09. http://clinicaltrials.gov and search on semustine or MeCCNU.
Delahunt B, Cartwright PR, Thornton A, Dady PJ. 1995. Proliferation kinetics of streptozotocin-induced renal tumours in mice. Virchows Arch. 425(6):577–582. 10.1007/BF00199345 7697213
Eisenbrand G. 1984. Anticancer nitrosoureas: Investigations on antineoplastic, toxic and neoplastic activities. IARC Sci Publ. (57):695–708. 6533062
FDA. 2009a. The Electronic Orange Book. U.S. Food and Drug Administration; Last accessed: 8/12/09. https://www.fda.gov/cder/ob/default.htm and select Search by Active Ingredient and search on semustine.
FDA. 2009b. The Electronic Orange Book. U.S. Food and Drug Administration; Last accessed: 8/12/09. https://www.fda.gov/cder/ob/default.htm and select Search by Active Ingredient and search on lomustine.
FDA. 2009c. Drugs@FDA. U.S. Food and Drug Administration; Last accessed: 8/12/09. https://www.accessdata.fda.gov/scripts/cder/drugsatfda/index.cfm?fuseaction=Search.Search_Drug_Name and search on carmustine.
FDA. 2009d. The Electronic Orange Book. U.S. Food and Drug Administration; Last accessed: 5/12/09. https://www.fda.gov/cder/ob/default.htm and select Search by Active Ingredient and search on chlorozotocin.
FDA. 2009e. Drugs@FDA. U.S. Food and Drug Administration; Last accessed: 8/12/09. https://www.accessdata.fda.gov/scripts/cder/drugsatfda/index.cfm?fuseaction=Search.Search_Drug_Name and search on lomustine.
FDA. 2009f. Drugs@FDA. U.S. Food and Drug Administration; Last accessed: 8/12/09. https://www.accessdata.fda.gov/scripts/cder/drugsatfda/index.cfm?fuseaction=Search.Search_Drug_Name and search on streptozotocin.
FDA. 2009g. The Electronic Orange Book. U.S. Food and Drug Administration; Last accessed: 8/12/09. https://www.fda.gov/cder/ob/default.htm and select Search by Active Ingredient and search on streptozotocin.
FDA. 2009h. The Electronic Orange Book. U.S. Food and Drug Administration; Last accessed: 8/12/09. https://www.fda.gov/cder/ob/default.htm and select Search by Active Ingredient and search on carmustine.
Feldman S, Scharp D, Hirshberg G, Dodi G, Ballinger W, Lacy P. 1977. Streptozotocin-induced liver tumors. Transplantation. 24(2):152–154. 10.1097/00007890-197708000-00010 143091
Habs M, Schmähl D. 1984. Long-term toxic and carcinogenic effects of cytostatic drugs. Dev Oncol. 15:201–209.
Hard GC. 1985. Identification of a high-frequency model for renal carcinoma by the induction of renal tumors in the mouse with a single dose of streptozotocin. Cancer Res. 45(2):703–708. 3155646
HSDB. 2009. Hazardous Substances Data Bank. National Library of Medicine; Last accessed: 8/12/09. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1974. Streptozotocin. In Some Aromatic Amines, Hydrazine and Related Substances, N-Nitroso Compounds and Miscellaneous Alkylating Agents. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans, vol. 4. Lyon, France: International Agency for Research on Cancer. pp. 221–227.
IARC. 1978. Streptozotocin. In Some N-Nitroso Compounds. IARC Monographs on the Evaluation of the Carcinogenic Risk of Chemicals to Humans, vol. 17. Lyon, France: International Agency for Research on Cancer. pp. 337–349.
IARC. 1981 a. Bischloroethyl nitrosourea (BCNU). In Some Antineoplastic and Immunosuppressive Agents. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans, vol. 26. Lyon, France: International Agency for Research on Cancer. pp. 79–95.
IARC. 1981 b. 1-(2-Chloroethyl)-3-cyclohexyl-1-nitrosourea (CCNU). In Some Antineoplastic and Immunosuppressive Agents. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans, vol. 26. Lyon, France: International Agency for Research on Cancer. pp. 137–149.
IARC. 1982 a. Bischloroethyl nitrosourea (BCNU). In Chemicals, Industrial Processes and Industries Associated with Cancer in Humans. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans, suppl. 4. Lyon, France: International Agency for Research on Cancer. pp. 63–64.
IARC. 1982 b. 1-(2-Chloroethyl)-3-cyclohexyl-1-nitrosourea (CCNU). In Chemicals, Industrial Processes and Industries Associated with Cancer in Humans. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans, suppl. 4. Lyon, France: International Agency for Research on Cancer. pp. 83–84.
IARC. 1987. Chloroethyl nitrosoureas: Bischloroethyl nitrosourea (BCNU) (Group 2A) 1-(2-chloroethyl)-3-cyclohexyl-1-nitrosourea (CCNU) (Group 2A) 1-(2-chloroethyl)-3-(4-methylcyclohexyl)-1-nitrosourea (methyl-CCNU) (Group 1). In Overall Evaluations of Carcinogenicity. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans, suppl. 7. Lyon, France: International Agency for Research on Cancer. pp. 150–152.
IARC. 1990. Chlorozotocin. In Pharmaceutical Drugs. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans, vol. 50. Lyon, France: International Agency for Research on Cancer. pp. 65–75.
Kazumi T, Yoshino G, Yoshida Y, Doi K, Yoshida M, Kaneko S, Baba S. 1978. Biochemical studies on rats with insulin-secreting islet cell tumors induced by streptozotocin: With special reference to physiological response to oral glucose load in the course of and after tumor induction. Endocrinology. 103(5):1541–1545. 10.1210/endo-103-5-1541 218781
Lemoine A, Lucas C, Ings RM. 1991. Metabolism of the chloroethylnitrosoureas. Xenobiotica. 21(6):775–791. 10.3109/00498259109039517 1949908
MedlinePlus. 2009a. Streptozotocin. National Library of Medicine; Last accessed: 8/12/09. https://www.nlm.nih.gov/medlineplus/druginfo/meds/a684053.html
MedlinePlus. 2009b. Carmustine. National Library of Medicine; Last accessed: 8/12/09. https://www.nlm.nih.gov/medlineplus/druginfo/meds/a682060.html
MedlinePlus. 2009c. Lomustine. National Library of Medicine; Last accessed: 8/12/09. https://www.nlm.nih.gov/medlineplus/druginfo/meds/a682207.html
NIOSH. 1990a. National Occupational Exposure Survey (1981-83). National Institute for Occupational Safety and Health; https://www.cdc.gov/noes/noes1/x5397sic.html
NIOSH. 1990b. National Occupational Exposure Survey (1981-83). National Institute for Occupational Safety and Health; https://www.cdc.gov/noes/noes1/x5492sic.html
NIOSH. 1990c. National Occupational Exposure Survey (1981-83). National Institute for Occupational Safety and Health; https://www.cdc.gov/noes/noes1/x3594sic.html
NIOSH. 1990d. National Occupational Exposure Survey (1981-83). National Institute for Occupational Health and Safety; https://www.cdc.gov/noes/noes1/x4755sic.html
NIOSH. 1990e. National Occupational Exposure Survey (1981-83). National Institute for Occupational Safety and Health; https://www.cdc.gov/noes/noes1/x1943sic.html
NIOSH. 2004. Antineoplastic Agents — Occupational Hazards in Hospitals. National Institute for Occupational Safety and Health; https://www.cdc.gov/niosh/docs/2004-102
Okawa H, Doi K. 1983. Neoplastic lesions in streptozotocin-treated rats. Jikken Dobutsu. 32(2):77–84. 10.1538/expanim1978.32.2_77 6225653
Parfitt K. 1999. Martindale: The Complete Drug Reference, 32nd ed. London, England: Pharmaceutical Press. p. 561.
Pauwels C, Rebischung JL, Jasmin C, Poupon MF. 1985. Enhanced cloning efficiency of murine rhabdomyosarcoma cells after chlorozotocin treatment: Relationship with enhanced lung metastasis. J Natl Cancer Inst. 74(4):817–820. 3157818
Pour PM, Kazakoff K, Carlson K. 1990. Inhibition of streptozotocin-induced islet cell tumors and N-nitrosobis(2-oxopropyl)amine-induced pancreatic exocrine tumors in Syrian hamsters by exogenous insulin. Cancer Res. 50(5):1634–1639. 2154330
Pour PM, Patil K. 1983. Modification of pancreatic carcinogenesis in the hamster model. X. Effect of streptozotocin. J Natl Cancer Inst. 71(5):1059–1065. 6316009
Rakieten N, Gordon BS. 1975. Metastatic renal adenocarcinoma produced by streptozotocin (NSC-85998). Cancer Chemother Rep. 59(5):891–892. 128413
SRI. 2009. Directory of Chemical Producers. Menlo Park, CA: SRI Consulting. Database edition; Last accessed: 8/12/09.
Weisburger EK. 1977. Bioassay program for carcinogenic hazards of cancer chemotherapeutic agents. Cancer. 40(4 Suppl):1935–1949. 10.1002/1097-0142(197710)40:4+<1935::AID-CNCR2820400827>3.0.CO;2-R 907995
Zimmerman PF, Larsen RK, Barkley EW, Gallelli JF. 1981. Recommendations for the safe handling of injectable antineoplastic drug products. Am J Hosp Pharm. 38(11):1693–1695. 10.1093/ajhp/38.11.1693 7304621